# Appendix E Chemical Characterization and Generation of Carousel Concentrations

## E.1 Procurement and Characterization of Bulk Fullerene C_60_

Fullerene C_60_ was obtained from SES Research (Houston, TX) in one lot (BT-6947). The study laboratory milled the test chemical in a ball mill to reduce particle size. After milling, initial purity and exposure testing revealed an insoluble impurity that was not present in the original unmilled material. The milled fullerene C_60_ was sent back to the manufacturer for repurification. The reprocessed fullerene C_60_ with the impurity removed (99.5% pure) was received from SES Research in one lot (BT-6947-Reprocess) that was used during the 3-month studies. Identity, purity, and moisture analyses were performed by the study laboratory at Battelle Toxicology Northwest [Richland, WA; high-performance liquid chromatography (HPLC) and gas chromatography (GC) analyses] and by the analytical chemistry laboratories at Cyanta Analytical Services [Maryland Heights, MO; Fourier transform infrared (FTIR) spectroscopy, elemental analyses, and Karl Fisher titration]; H & M Analytical Services, Inc. [Allentown, NJ; X-ray diffraction (XRD) analysis]; and Pacific Northwest National Laboratory (Richland, WA; laser Raman analysis). Reports on analyses performed in support of the fullerene C_60_ studies are on file at the National Institute of Environmental Health Sciences.

Lot BT-6947-Reprocess of the chemical, a black solid with no detectable odor, was identified as fullerene C_60_ by FTIR and laser Raman spectroscopy and XRD analyses. The FTIR and laser Raman spectra of the test chemical were consistent with literature spectra (FTIR; Nakamoto and McKinney^65^) and the structure and composition of fullerene C_60_. XRD with Rietveld analysis showed only the face-centered cubic polymorph of fullerene C_60_. Representative FTIR, laser Raman, and XRD spectra are presented in Figure E-1, Figure E-2, and Figure E-3, respectively.

Karl Fischer titration was used to determine the water content of lot BT-6947-Reprocess. The purity of the bulk chemical was determined by elemental analysis, GC by system A, and HPLC by system B.

A) Agilent gas chromatograph (model 6890; Agilent Technologies, Inc., Palo Alto, CA), a DB-5 (30 m × 0.53 mm ID, 5.0 µm film thickness) column (J&W Scientific, Folsom, CA), flame ionization detection (FID), helium as the carrier gas at 6.0 psi head pressure, and an oven temperature program of 45°C for 10 minutes, then 20°C/minute to 270°C, then held for 10 minutes

B) Agilent high-performance liquid chromatograph (model 1100; Agilent Technologies, Inc.), a Buckyprep (4.6 mm × 250 mm) column (Waters Corporation, Milford, MA), a mobile phase of A) n-hexane:toluene (70:30) and B) toluene:chlorobenzene (70:30) with a linear gradient program of 100% A to 100% B in 30 minutes, held for 30 minutes, to 100% A in 5 minutes, held for 5 minutes, with ultraviolet/visible detection at 330 nm, and a flow rate of 1.0 mL/minute

For lot BT-6947-Reprocess, Karl Fischer titration indicated a water content of less than 900 ppm. Elemental analyses showed a composition of 99.7% carbon, 0.24% nitrogen, less than 0.1% hydrogen, and less than 300 ppm sulfur. GC/FID by system A indicated one residual solvent, 1,2,4-trimethylbenzene (TMB) at 0.8% (predrying) and 0.6% (postdrying). HPLC by system B indicated an area percent purity of 98.5%. The overall purity of lot BT-6947-Reprocess was determined to be at least 98.5%.

To ensure stability, the bulk chemical was stored at room temperature in amber glass containers. Periodic reanalyses of the bulk chemical were performed during the 3-month studies by the study laboratory using HPLC by system B; no degradation of the bulk chemical was detected.

## E.2 Aerosol Generation and Exposure System for the Micro-C_60_ Studies

A diagram of the fullerene C_60_ (1 µm) aerosol generation and delivery system used in the studies is shown in Figure E-4. The system used a linear feed powder-metering device, particle attrition chamber, dispersion jet, and cyclone separator all located within a glove box in the exposure room. The air-driven shuttle bar in the powder-metering device dispersed the bulk material at timed intervals into a nitrogen gas stream; the nitrogen gas was used to minimize oxidation of the test chemical during the vaporization phase. The material suspended in the gas stream was further reduced in size by passing through the particle attrition chamber, which used a pressurized nitrogen stream to promote particle-to-particle impaction, breaking apart the particles. A high-pressure dispersion jet at the output of the particle attrition chamber added dispersion energy to drive the aerosol into the cyclone separator, which removed unwanted large particles from the aerosol stream. The aerosol stream from the glove box was directed to a residence chamber to allow for additional separation of larger particles by gravitational settling. The residence chamber was monitored to maintain generator output consistency using a real-time aerosol monitor (RAM) (Micro Dust pro, Casella USA, Amherst, NH), and material in excess of that required to maintain the exposure units at target concentrations was withdrawn through high-efficiency particulate air (HEPA) filters prior to delivery to the residence chamber. Aerosol was delivered from the residence chamber to each exposure carousel through a metering element that fixed the flow to each carousel. Humidified air was added to the aerosol-laden air downstream from the metering element to provide dilution and humidify the airstream. Concentration was controlled by siphoning excess delivery flow from a point following the metering element but before the introduction of dilution air. Past the dilution air input, aerosol-laden air was directed to a computer-controlled pneumatic slide valve that served as the on/off control valve for the flow through a dedicated distribution system branch line to each exposure carousel.

The rodent exposure carousel was developed by the study laboratory and consisted of stackable tiers with 16 nose-only exposure ports per tier. Each carousel consisted of five tiers thus providing 80 ports for animal exposure. One end of the tube that served to restrain the individual was tapered to approximately fit the shape of the animal’s head and the diameter of the remaining cylindrical portion of the tube made it difficult for the animal to turn in the tube. The back portion of the tube was covered with a plastic cap, and tubes containing animals were fastened to the inhalation carousel by means of a bracket, ensuring the nose portion of the tube protruded through a gasket and into the carousel.

The test aerosol entered the carousel through the top and then flowed out radially to each of the 16 evenly spaced exposure ports per tier. Each port received approximately 500 mL/minute of exposure atmosphere, which equated to a total exposure unit inlet flow of 40 L/minute. Ports not used for animal exposure or sampling were closed. This design provided uniform concentration and fresh test chemical to each animal connected to the exposure system and minimized any effect of the animals on the atmosphere because no exhaled air from one animal could reach the breathing zone of another. Each exposure carousel was surrounded by a temperature-controlled ventilated enclosure that minimized the release of aerosol from the carousel to the room and provided a means of cooling the animals confined to the nose tubes.

## E.3 Aerosol Generation and Exposure System for the Nano-C_60_ Studies

A diagram of the fullerene C_60_ (50 nm) aerosol generation and delivery system used in the studies is shown in Figure E-5. The aerosol generation and delivery system used the same glove box and residence chamber components as described for the micro-C_60_ studies; but for the nano-C_60_ studies, the aerosol-laden airstream from the residence chamber was directed into four identically configured delta tubes designed to provide a metered flow in relation to the pressure drop maintained in the residence chamber. Downstream from each delta tube, a flowmeter-controlled siphon allowed for regulation of the flow into quartz tube furnaces present at a target of approximately 520°C for flash vaporization of the test article. Near the exit of each furnace tube, additional nitrogen gas was introduced into the flow to rapidly cool the vaporized test material, condensing it into nanometer-sized particles. The additional nitrogen also increased the velocity of the carrier stream, diluted the concentration of the particles, and reduced the opportunity for particle agglomeration. Humidified air was added to the aerosol-laden nitrogen gas stream that exited each furnace tube to provide additional dilution, cooling, humidification, and oxygenation to the exposure atmosphere.

Subsequent aerosol flow through the computer-controlled pneumatic slide valves and exposure carousels was as described for the micro-C_60_ studies except that a second siphon and dilution air assembly was located just prior to the slide valves to further reduce aerosol concentrations in the test atmosphere. Exposure carousels for the nano-C_60_ studies provided a total of 40 ports for animal exposure via 8 ports on each of the 5 tiers.

## E.4 Aerosol Concentration Monitoring for the Micro-C_60_ and Nano-C_60_ Studies

Summaries of the carousel aerosol concentrations are presented in Table E-1 and Table E-2. For the micro-C_60_ studies, micrometer-sized fullerene C_60_ aerosol was monitored for concentration using an online RAM (MicroDust pro; Casella USA). For the nano-C_60_ studies, nanometer-sized fullerene C_60_ was similarly monitored using a RAM-1 instrument (MIE, Inc., Bedford, MA). The analog output voltage from each RAM was recorded by the Battelle Exposure Data Acquisition and Control (BEDAC) software system and converted to mg/m^3^ exposure concentration by the application of a calibration curve. During the studies, if a measured concentration exceeded its allowed limits, the BEDAC program triggered an audible alarm or, in extreme cases, terminated the exposure.

RAM calibrations were performed by constructing response curves using RAM voltage recorded each day at the time duplicate atmosphere samples were collected from each exposure carousel on 25 mm Teflon^®^-coated glass-fiber filters (Pallflex^®^ Emfab™ TX40HI20WW filters; Pall Corporation, Ann Arbor, MI); RAM voltages were corrected for zero-offset voltage measured in a HEPA-filtered airstream. Fullerene C_60_ collected on the filters from each exposure carousel was dissolved in a 50:50 mixture of TMB:toluene containing a known amount of internal standard (fullerene-C70; MER Corporation, Tucson, AZ) and quantified using HPLC by system C on an off-line chromatograph.

C) Agilent high-performance liquid chromatograph (model 1100; Agilent Technologies, Inc.), a Buckyprep (4.6 mm × 250 mm) column (Waters Corporation), an isocratic mobile phase of 100% toluene, ultraviolet/visible detection at 330 nm, and a flow rate of 1.0 mL/minute

The off-line chromatograph was calibrated using gravimetrically prepared standard solutions of the test article and the internal standard in 50:50 TMB:toluene. These methods were demonstrated by the study laboratory to have adequate precision, accuracy, linear working range, day-to-day repeatability, and detection limits for measuring 1 µm and 50 nm fullerene C_60_ concentrations in the exposure carousels.

## E.5 Carousel Atmosphere Characterization or the Micro-C_60_ and Nano-C_60_ Studies

Aerosol particle size distribution was determined once prior to and approximately monthly during the micro-C_60_ studies by collecting aerosol samples from each exposure carousel (except the 0 mg/m^3^ carousels) using a Mercer style cascade impactor. Fullerene C_60_ was collected on stages one through seven within the impactor on 22 mm diameter stainless steel slides (In-Tox Products, Moriarty, NM) coated with silicone spray. The final, stage eight sample was collected on a 25 mm diameter Pallflex^®^ Emfab™ glass-fiber filter (Pall Corporation). Collected aerosol was dissolved in a 50:50 mixture of TMB:toluene and assayed for mass of test material using HPLC by system C. The relative mass collected on each stage was analyzed by the probit-based CASPACT impactor analysis program developed at the study laboratory^66^ to yield estimates of the mass median aerodynamic diameter (MMAD) of the particles.

The surface-area-to-mass ratio of micrometer-sized particles was estimated using data derived from the Mercer cascade impactor data and carousel mass concentrations. Mass median diameter (MMD) was calculated from MMAD using the Hatch-Choate relationships for log-normal distributions. Count median diameter (CMD) was calculated from MMD. The average surface area particle diameter (d_s_) and the average mass particle diameter (d_m_) were calculated from CMD, assuming a spherical particle shape. The surface area per particle was calculated from d_s_. The total number of particles per volume of air was calculated from d_m_ and the aerosol concentration determined from the RAM data. Once the total number of particles per volume of air was determined, the surface area per particle was multiplied by this value to obtain total surface area per volume of air. Total surface area per volume of air was divided by total mass per volume of air to obtain total surface area to total mass. Estimates of particle sizes and surface-area-to-mass ratios during the micro-C_60_ studies are presented in Table E-3; MMAD values fell well below the 3.0 µm upper limit criterion required by the design of the studies.

For the nano-C_60_ studies, aerosol particle size distribution was initially measured without animals in the exposure carousels during prestart studies using a Model 125B NanoMOUDI™ Low Pressure Cascade Impactor (MSP Corporation, Shoreview, MN). The NanoMOUDI™ classified particles according to aerodynamic size by inertial impaction in several multinozzle stages stacked in series; the chemically analyzed relative mass collected on each impactor stage was analyzed from a validated spreadsheet using the manufacturer’s values for impactor stage effective cutoff diameter. Data from this impactor resulted in a true measurement of MMAD for the aerosolized test article in each exposure carousel, but the device could not be used with animals in the exposure carousels because diversion of approximately half the aerosol flow to each carousel was required for proper functioning of the impactor. Accordingly, size distribution of the nano-C_60_ particles was also measured using a Scanning Mobility Particle Sizer (SMPS™; TSI^®^, Inc., Shoreview, MN) that combined particle sizing by electrical mobility with condensation particle counting. The primary measurement output of the SMPS™ was particle CMD. MMD was calculated from measured CMD and the associated geometric standard deviation (GSD) using Hatch-Choate relationships assuming log-normal aerosol size distribution and then converted to MMAD assuming a particle density of 1.72 g/cc. By these means, a correlation was established between the results of NanoMOUDI™ impactor and SMPS™ analyses enabling the use of the SMPS™ during the animal exposures to provide estimates of particle size distribution.

Measurements of particle size during animal exposures were conducted daily during the nano-C_60_ studies using the SMPS™. Monthly averaged results for these measurements in each exposure carousel during the 3-month nano-C_60_ studies are presented in Table E-4 and demonstrate that the particles delivered to each exposure unit were nanometer sized.

The surface-area-to-mass ratios of nanometer-sized particles in the nano-C_60_ studies were estimated using data derived from the SMPS™ CMD and carousel exposure concentration using the same calculations as described for the micrometer-sized particles. The results are presented in Table E-5.

Buildup and decay rates for carousel aerosol concentrations were not determined. For nose-only carousels, the time for the concentration to reach 90% of its stable final concentration after start of exposure (T_90_) is less than the resolving ability of the measurement instrumentation and is calculated at <2 seconds. For this reason, no measurements of T_90_ or the time for the concentration to reach 10% of the concentration determined immediately before termination of the exposure (T_10_) were performed.

Uniformity of the aerosol concentration in the inhalation exposure carousels without animals present was evaluated before the 3-month micro-C_60_ and nano-C_60_ studies began. The aerosol concentration was measured using the online monitor with continuous monitoring from the input line. Measurements were taken from carousel exposure ports located on the top, middle, and bottom tiers of the carousel. For the micro-C_60_ studies, total port variability (TPV) for the three carousels ranged from 4.0% to 4.7% relative standard deviation (RSD), and for the nano-C_60_ studies, TPV for the four carousels ranged from 4.3% to 4.8% RSD.

Uniformity of aerosol concentration in the inhalation exposure carousels during the animal studies was not evaluated.

Fullerene C_60_ was determined to be stable under the generation and exposure conditions used during the 3-month studies by analyses conducted before and during the 3-month studies by the study laboratory and the analytical chemistry laboratories. Samples were collected and analyzed from all exposure carousels and from the generator reservoir; during the 3-month studies, bulk fullerene C_60_ in the generator reservoir was refilled as needed, and the analysis sample was collected from the reservoir at the end of the day after it was placed in service. Analyses included HPLC by system B for area percent purity, GC with mass spectrometry (MS) detection by system D for determination of residual TMB (not performed on reservoir samples before the 3-month studies), inductively coupled plasma/atomic emission spectroscopy (ICP/AES) by system E for elemental analysis, and XRD and laser Raman spectroscopy for characterization of the form of the test material.

D) Agilent gas chromatograph/mass spectrometer (model 6890/5973; Agilent Technologies, Inc.), a DB-5 (30 m × 0.25 mm ID, 0.25 µm film thickness) column (J&W Scientific), MS detection using electron impact ionization with selected ion monitoring, helium as the carrier gas flowing at 0.9 mL/minute, and an oven temperature program of 45°C for 10 minutes, then 20°C/minute to 270°C, then held for 10 minutes, or 45°C for 1 minute, then 20°C to 150°C, then held for 1 minute

E) Thermo Elemented IRIS Intrepid inductively coupled plasma/atomic emission spectrometer (Thermo Fisher Scientific, Waltham, MA), a nebulizer operated at 0 to 200 rpm and 15 to 45 psi, and a radio-frequency generator powered at 750 to 1,750 watts. This system was calibrated with traceable reference standards obtained from the National Institute of Standards and Technology

Exposure atmosphere samples were collected from all rat and mouse carousels on 25 mm glass-fiber Teflon^®^-coated filters (PallFlex^®^ Emfab™, Pall Corporation) for HPLC and ICP/AES analyses, and on A/E glass-fiber filters (Pall Corporation) for XRD and laser Raman analyses. Atmosphere samples for GC/MS analyses were collected on activated coconut charcoal sorbent tubes (ORBO™ 32s; Supelco, Inc., Bellefonte, PA).

For area percent purity assessments, filters and generator reservoir samples were extracted with TMB:toluene (50:50). For determination of TMB as a residue of repurification of the bulk test material, the sorbent tubes and generator reservoir samples were extracted with carbon disulfide. For elemental analysis, samples were microwave-digested in concentrated HCl:HNO_3_ (2:1) containing indium as an internal standard, filtered through Teflon^®^-coated syringe filters (Acrodisc^®^CR, 25 mm, 0.45 µm; Pall Corporation), and analyzed for the concentration of 15 elements.

XRD with Rietveld analysis indicated that the principal crystalline phase in samples from the generator reservoir and exposure atmosphere samples from all carousels both before and during the 3-month micro- and nano-C_60_ studies in rats and mice was the disordered face-centered cubic form of fullerene C_60_. The XRD-determined purity of all generator reservoir and atmosphere samples exceeded 99.7% and 98%, respectively. Laser Raman assays concluded that all elemental carbon in the samples was in the form of C_60_ fullerene. Using HPLC by system B, average area percent purity for the generator reservoir samples exceeded 98% prior to and during all studies. Area percent purity for the atmosphere samples collected from all carousels prior to and during the micro-C_60_ studies exceeded 98%; similar measurements prior to and during the nano-C_60_ studies indicated an exposure atmosphere purity of 99% or greater. GC/MS by system D detected 0.6% TMB in all reservoir samples collected during the 3-month studies. TMB concentrations in atmosphere samples ranged from 0.4% to 0.6% prior to and during the micro-C_60_ studies and from 0.6% to 2.5% prior to and during the nano-C_60_ studies. ICP/AES analyses by system E showed no elemental contamination in either the generator reservoir or exposure atmosphere samples collected before or during each study.

Table E-1 Summary of Carousel Concentrations in the Three-month Nose-only Inhalation Studies of Fullerene Micro-C_60_ (1 μm)

| Target Concentration (mg/m^3^) | Total Number of Readings | Average Concentration^a^ (mg/m^3^)
Rat Carousels
| 2 | 3,350 | 2.0 ± 0.2
| 15 | 3,368 | 14.7 ± 1.2
| 30 | 3,360 | 30.7 ± 1.8
Mouse Carousels
| 2 | 3,327 | 2.1 ± 0.2
| 15 | 3,341 | 14.6 ± 1.1
| 30 | 3,328 | 30.2 ± 1.8

^a^ Mean ± standard deviation.

Table E-2 Summary of Carousel Concentrations in the Three-month Nose-only Inhalation Studies of Fullerene Nano-C_60_ (50 nm)

| Target Concentration (mg/m^3^) | Total Number of Readings | Average Concentration^a^ (mg/m^3^)
Rat Carousels
Male
| 0.5 | 3,280 | 0.50 ± 0.07
| 2.0 | 3,287 | 2.00 ± 0.23
Female
| 0.5 | 3,278 | 0.50 ± 0.07
| 2.0 | 3,282 | 2.01 ± 0.24
Mouse Carousels
Male
| 0.5 | 3,318 | 0.50 ± 0.07
| 2.0 | 3,327 | 2.01 ± 0.23
Female
| 0.5 | 3,317 | 0.50 ± 0.07
| 2.0 | 3,332 | 2.00 ± 0.23

^a^ Mean ± standard deviation.

Table E-3 Summary of Aerosol Size Measurements and Aerosol Surface-Area-to-Mass Ratios for the Rat and Mouse Exposure Carousels in the Three-month Nose-only Inhalation Studies of Fullerene Micro-C_60_ (1 μm)^a^

Target Concentration (mg/m^3^) | November 12–13, 2007 | | December 10-11, 2007 | | January 8–9, 2008 | | Surface-Area-to-Mass Ratio^b^ (m^2^/g)
Target Concentration (mg/m^3^) | MMAD (μm) | GSD | MMAD (µm) | GSD | MMAD (μm) | GSD | Surface-Area-to-Mass Ratio^b^ (m^2^/g)
Rat Carousels
2 | 1.19 | 2.26 | 1.15 | 2.21 | 1.11 | 2.15 | 5.4
15 | 1.18 | 2.41 | 1.04 | 2.28 | 1.20 | 2.34 | 5.8
30 | 1.19 | 2.42 | 1.17 | 2.30 | 1.20 | 2.32 | 5.5
Mouse Carousels
2 | 1.43 | 2.43 | 1.25 | 2.28 | 1.11 | 2.18 | 5.1
15 | 1.28 | 2.52 | 1.21 | 2.42 | 1.27 | 2.36 | 5.4
30 | 1.25 | 2.54 | 1.19 | 2.34 | 1.16 | 2.36 | 5.6

MMAD = mass median aerodynamic diameter; GSD = geometric standard deviation.

^a^ Aerosol samples were collected three times during the studies with animals present in the carousels.

^b^ Surface areas were calculated from averaged monthly cascade impactor data.

Table E-4 Summary of Aerosol Size Measurements for the Rat and Mouse Exposure Carousels in the Three-month Nose-only Inhalation Studies of Fullerene Nano-C_60_ (50 nm)^a^

Target Concentration (mg/m^3^)/Carousel Number | CMD (nm) | GSD | MMAD (nm) | CMD (nm) | GSD | MMAD (nm) | CMD (nm) | GSD | MMAD (nm)
Rat Carousels | November 14, 2007 | | | December 14, 2007 | | | January 10, 2008
0.5/1 | 36 | 1.6 | 85 | 38 | 1.6 | 93 | 35 | 1.5 | 69
0.5/2 | 36 | 1.4 | 70 | 33 | 1.5 | 69 | 35 | 1.4 | 67
2.0/1 | 46 | 1.5 | 91 | 43 | 1.5 | 85 | 45 | 1.5 | 91
2.0/2 | 45 | 1.5 | 94 | 41 | 1.5 | 81 | 43 | 1.5 | 86
Mouse Carousels | November 13, 2007 | | | December 13, 2007 | | | January 9, 2008
0.5/1 | 31 | 1.6 | 79 | 37 | 1.5 | 86 | 34 | 1.5 | 72
0.5/2 | 35 | 1.5 | 72 | 35 | 1.5 | 79 | 33 | 1.4 | 64
2.0/1 | 45 | 1.5 | 93 | 45 | 1.5 | 93 | 44 | 1.5 | 87
2.0/2 | 39 | 1.5 | 80 | 44 | 1.5 | 89 | 42 | 1.5 | 85

CMD = count median diameter; GSD = geometric standard deviation; MMAD = mass median aerodynamic diameter.

^a^ Aerosol samples were collected daily during the studies (monthly averages are presented here) with animals present in the carousels.

Table E-5 Summary of Aerosol Surface-Area-to-Mass Ratios for the Rat and Mouse Exposure Carousels in the Three-month Nose-only Inhalation Studies of Fullerene Nano-C_60_ (50 nm)^a^

Target Concentration (mg/m^3^)/Carousel Number | Surface-Area-to-Mass Ratio (m^2^/g)
Rat Carousels | November 14, 2007 | December 14, 2007 | January 10, 2008
0.5/1 | 59 | 55 | 71
0.5/2 | 70 | 72 | 73
2.0/1 | 54 | 58 | 54
2.0/2 | 53 | 60 | 57
Mouse Carousels | November 13, 2007 | December 13, 2007 | January 9, 2008
0.5/1 | 65 | 59 | 69
0.5/2 | 68 | 63 | 76
2.0/1 | 53 | 53 | 56
2.0/2 | 62 | 56 | 58

^a^ Aerosol samples were collected daily during the studies (monthly averages are presented here) with animals present in the carousels.

Figure E-1

Infrared Absorption Spectrum of Bulk Fullerene C_60_

Figure E-2

Laser Raman Spectrum of Bulk Fullerene C_60_

Figure E-3

X-ray Diffraction Pattern of Bulk Fullerene C_60_

The stick pattern shown under the spectral peaks of this expanded view are the theoretical diffraction patterns of fullerene C_60_.

Figure E-4

Schematic of the Aerosol Generation and Delivery System in the Three-month Nose-only Inhalation Studies of Fullerene Micro-C_60_ (1 μm)

Figure E-5

Schematic of the Aerosol Generation and Delivery System in the Three-month Nose-only Inhalation Studies of Fullerene Nano-C_60_ (50 nm)