# Appendix D Genetic Toxicology

Table D-1 Frequency of Micronucleated Erythrocytes in Peripheral Blood of Rats Following Treatment with Fullerene Micro-C_60_ (1 µm) by Nose-only Inhalation for Three Months^a^

| Concentration (mg/m^3^) | Number of Rats with Erythrocytes Scored | Micronucleated PCEs/1,000 PCEs^b^ | P Value^c^ | Micronucleated NCEs/1,000 NCEs^b^ | P Value^c^ | PCEs^b^ (%) | P Value^c^
Male
Air^d^ | 0 | 5 | 0.74 ± 0.12 | | 0.03 ± 0.01 | | 0.989 ± 0.07
Fullerene C_60_ | 2 | 5 | 0.62 ± 0.10 | 1.0000 | 0.05 ± 0.02 | 0.1780 | 1.050 ± 0.12 | 0.7245
| 15 | 5 | 0.88 ± 0.18 | 0.8863 | 0.06 ± 0.01 | 0.1503 | 1.135 ± 0.06 | 0.3396
| 30 | 5 | 0.60 ± 0.09 | 1.0000 | 0.04 ± 0.01 | 0.1599 | 1.124 ± 0.10 | 0.3616
| | | p = 0.607^e^ | | p = 0.395^f^ | | p =0.252^f^
Female
Air | 0 | 5 | 0.62 ± 0.09 | | 0.08 ± 0.02 | | 1.243 ± 0.10
Fullerene C_60_ | 2 | 5 | 0.79 ± 0.14 | 0.1737 | 0.04 ± 0.01 | 0.8514 | 1.272 ± 0.10 | 0.9531
| 15 | 5 | 0.94 ± 0.17 | 0.1268 | 0.04 ± 0.01 | 0.9125 | 1.338 ± 0.25 | 0.9947
| 30 | 5 | 0.76 ± 0.06 | 0.1342 | 0.07 ± 0.01 | 0.7281 | 1.225 ± 0.12 | 0.9908
| | | p = 0.266^f^ | | p = 0.372^f^ | | p = 0.845^f^

NCE = normochromatic erythrocyte; PCE = polychromatic erythrocyte.

^a^ Study was performed at ILS, Inc. The detailed protocol is presented by Witt et al.^82^

^b^ Mean ± standard error.

^c^ Pairwise comparison with the control group; significant if p ≤ 0.025 by Dunn’s or Williams’ test.

^d^ Control.

^e^ Significance tested by Jonckheere’s trend test; significant if p ≤ 0.025.

^f^ Significance tested by a linear regression trend test; significant if p ≤ 0.025.

Table D-2 Frequency of Micronucleated Erythrocytes in Peripheral Blood of Rats Following Treatment with Fullerene Nano-C_60_ (50 nm) by Nose-only Inhalation for Three Months^a^

| Concentration (mg/m^3^) | Number of Rats with Erythrocytes Scored | Micronucleated PCEs/1,000 PCEs^b^ | P Value^c^ | Micronucleated NCEs/1,000 NCEs^b^ | P Value^c^ | PCEs^b^ (%) | P Value^c^
Male
Air^d^ | 0 | 5 | 0.84 ± 0.13 | | 0.06 ± 0.01 | | 0.930 ± 0.10
Fullerene C_60_ | 0.5 | 5 | 0.73 ± 0.16 | 0.5925 | 0.06 ± 0.01 | 0.7256 | 0.867 ± 0.06 | 0.7408
| 2 | 5 | 0.84 ± 0.19 | 0.5837 | 0.03 ± 0.00 | 0.8077 | 0.883 ± 0.11 | 0.8437
| | | p = 0.438^e^ | | p = 0.983 | | p = 0.763
Female
Air | 0 | 5 | 0.87 ± 0.07 | | 0.13 ± 0.03 | | 1.044 ± 0.08
Fullerene C_60_ | 0.5 | 5 | 0.83 ± 0.10 | 0.6902 | 0.05 ± 0.01 | 0.9586 | 1.038 ± 0.07 | 0.9775
| 2 | 5 | 0.74 ± 0.07 | 0.7746 | 0.05 ± 0.01 | 0.9824 | 1.026 ± 0.15 | 0.8548
| | | p = 0.883 | | p = 0.963 | | p = 0.701

NCE = normochromatic erythrocyte; PCE = polychromatic erythrocyte.

^a^ Study was performed at ILS, Inc. The detailed protocol is presented by Witt et al.^82^

^b^ Mean ± standard error.

^c^ Pairwise comparison with the control group; significant if p ≤ 0.025 by Williams’ test.

^d^ Control group.

^e^ Significance tested by a linear regression trend test; significant if p ≤ 0.025.

Table D-3 Frequency of Micronucleated Erythrocytes in Peripheral Blood of Mice Following Treatment with Fullerene Micro-C_60_ (1 µm) by Nose-only Inhalation for Three Months^a^

| Concentration (mg/m^3^) | Number of Mice with Erythrocytes Scored | Micronucleated PCEs/1,000 PCEs^b^ | P Value^c^ | Micronucleated NCEs/1,000 NCEs^b^ | P Value^c^ | PCEs^b^ (%) | P Value^c^
Male
Air^d^ | 0 | 5 | 2.72 ± 0.12 | | 1.49 ± 0.05 | | 1.494 ± 0.12
Fullerene C_60_ | 2 | 5 | 2.67 ± 0.19 | 0.5642 | 1.38 ± 0.05 | 0.8838 | 1.786 ± 0.14 | 0.5306
| 15 | 5 | 2.66 ± 0.20 | 0.6514 | 1.38 ± 0.03 | 0.9366 | 1.761 ± 0.10 | 0.6337
| 30 | 5 | 2.98 ± 0.11 | 0.1776 | 1.39 ± 0.05 | 0.9527 | 1.372 ± 0.16 | 0.5467
| | | p = 0.100^e^ | | p = 0.835^e^ | | p = 0.204^e^
Female
Air | 0 | 5 | 1.68 ± 0.09 | | 1.00 ± 0.01 | | 1.428 ± 0.09
Fullerene C_60_ | 2 | 5 | 2.32 ± 0.18 | 0.0276 | 1.04 ± 0.03 | 0.5886 | 1.617 ± 0.09 | 0.4532
| 15 | 5 | 1.85 ± 0.09 | 0.0328 | 0.97 ± 0.01 | 1.0000 | 1.642 ± 0.18 | 0.5448
| 30 | 5 | 2.00 ± 0.13 | 0.0348 | 1.00 ± 0.02 | 1.0000 | 1.588 ± 0.20 | 0.5801
| | | p = 0.485^e^ | | p = 0.770^f^ | | p = 0.788^e^

NCE = normochromatic erythrocyte; PCE = polychromatic erythrocyte.

^a^ Study was performed at ILS, Inc. The detailed protocol is presented by Witt et al.^82^

^b^ Mean ± standard error.

^c^ Pairwise comparison with the control group; significant if p ≤ 0.025 by Dunn’s or Williams’ test.

^d^ Control group.

^e^ Significance tested by a linear regression trend test; significant if p ≤ 0.025.

^f^ Significance tested by Jonckheere’s trend test; significant if p ≤ 0.025.

Table D-4 Frequency of Micronucleated Erythrocytes in Peripheral Blood of Mice Following Treatment with Fullerene Nano-C_60_ (50 nm) by Nose-only Inhalation for Three Months^a^

| Concentration (mg/m^3^) | Number of Mice with Erythrocytes Scored | Micronucleated PCEs/1,000 PCEs^b^ | P Value^c^ | Micronucleated NCEs/1,000 NCEs^b^ | P Value^c^ | PCEs^b^ (%) | P Value^c^
Male
Air^d^ | 0 | 5 | 2.42 ± 0.22 | | 1.54 ± 0.08 | | 1.559 ± 0.06
Fullerene C_60_ | 0.5 | 5 | 2.33 ± 0.09 | 0.5650 | 1.48 ± 0.02 | 0.7532 | 1.683 ± 0.07 | 0.3173
| 2 | 5 | 2.50 ± 0.22 | 0.4558 | 1.44 ± 0.02 | 0.8323 | 1.615 ± 0.05 | 0.3814
| | | p = 0.327^e^ | | p = 0.889^e^ | | p = 0.765^e^
Female
Air | 0 | 5 | 2.03 ± 0.08 | | 1.05 ± 0.03 | | 1.583 ± 0.10
Fullerene C_60_ | 0.5 | 5 | 1.92 ± 0.22 | 0.7029 | 1.02 ± 0.01 | 0.6615 | 1.741 ± 0.04 | 0.5777
| 2 | 5 | 1.77 ± 0.14 | 0.7871 | 1.09 ± 0.03 | 0.1005 | 1.715 ± 0.21 | 1.0000
| | | p = 0.872^e^ | | p = 0.043^e^ | | p = 0.634^f^

NCE = normochromatic erythrocyte; PCE = polychromatic erythrocyte.

^a^ Study was performed at ILS, Inc. The detailed protocol is presented by Witt et al.^82^

^b^ Mean ± standard error.

^c^ Pairwise comparison with the control group; values are significant if p ≤ 0.025 by Dunn’s or Williams’ test.

^d^ Control.

^e^ Significance tested by a linear regression trend test; significant if p ≤ 0.025.

^f^ Significance tested by Jonckheere’s trend test; significant if p ≤ 0.025.