# Appendix C Immunotoxicity Results

Table C-1 Spleen Cell Immunophenotypes in Female Rats and Mice in the Three-month Nose-only Inhalation Studies of Fullerene Nano-C_60_ (50 nm) and Micro-C_60_ (1 μm)^a^

| 50 nm C_60_ 0 mg/m^3^ | 50 nm C_60_ 0.5 mg/m^3^ | 50 nm C_60_ 2 mg/m^3^ | 1.0 µm C_60_ 0 mg/m^3^ | 1.0 µm C_60_ 2 mg/m^3^ | 1.0 µm C_60_ 15 mg/m^3^ | 1.0 µm C_60_ 30 mg/m^3^
n | 8 | 8 | 8 | 8 | 8 | 8 | 8
Female Rats
Total Spleen Cells (×10^7^) | 31.82 ± 2.27 | 31.68 ± 3.45 | 29.57 ± 2.86 | 28.27 ± 1.14 | 31.68 ± 1.75 | 31.46 ± 1.55 | 33.22 ± 2.95
CD45+
Absolute | 124.3 ± 8.9 | 130.7 ± 16.2 | 110.0 ± 13.2 | 106.7 ± 4.5 | 121.1 ± 11.3 | 119.4 ± 6.8 | 133.1 ± 12.0
Percent | 39.2 ± 1.4 | 41.6 ± 2.5 | 36.9 ± 1.4 | 38.0 ± 1.9 | 38.1 ± 2.5 | 38.0 ± 1.5 | 40.1 ± 1.4
CD5+
Absolute | 106.0 ± 7.2 | 103.6 ± 13.7 | 86.6 ± 12.4 | 84.0 ± 10.2 | 99.4 ± 7.2 | 94.3 ± 4.2 | 101.5 ± 10.5
Percent | 33.4 ± 1.2 | 33.3 ± 3.2 | 28.9 ± 2.4 | 29.5 ± 3.2 | 32.0 ± 2.7 | 30.1 ± 1.1 | 30.3 ± 0.7
CD4+CD5+
Absolute | 62.9 ± 3.7^▲^ | 59.8 ± 6.6 | 50.3 ± 7.7 | 47.9 ± 5.7 | 57.1 ± 3.4 | 52.6 ± 3.8 | 61.1 ± 6.7
Percent | 20.0 ± 0.7^▲^ | 19.4 ± 1.5 | 16.7 ± 1.2 | 16.8 ± 1.8 | 18.3 ± 1.3 | 16.7 ± 1.0 | 18.2 ± 0.7
CD8+CD5+
Absolute | 40.6 ± 4.2 | 39.7 ± 6.4 | 33.9 ± 5.4 | 31.6 ± 4.6 | 39.7 ± 5.3 | 33.1 ± 2.1 | 35.5 ± 4.6
Percent | 12.6 ± 0.8 | 12.8 ± 1.7 | 11.3 ± 1.3 | 11.1 ± 1.5 | 12.8 ± 1.8 | 10.6 ± 0.7 | 10.5 ± 0.6
NK+CD8+
Absolute | 9.0 ± 0.9 | 10.3 ± 1.3 | 9.0 ± 0.7 | 10.2 ± 1.0 | 10.8 ± 1.2 | 12.1 ± 1.9 | 9.9 ± 1.5
Percent | 2.9 ± 0.3 | 3.3 ± 0.3 | 3.1 ± 0.2 | 3.6 ± 0.4 | 3.4 ± 0.4 | 3.8 ± 0.5 | 3.1 ± 0.6
HIS6+
Absolute | 14.3 ± 1.2 | 12.0 ± 1.4 | 13.5 ± 1.2 | 9.6 ± 1.0 | 14.6 ± 1.9 | 15.7 ± 1.9*^b^ | 11.8 ± 1.6
Percent | 4.5 ± 0.3 | 3.9 ± 0.5 | 4.8 ± 0.4 | 3.4 ± 0.3 | 4.5 ± 0.4 | 5.1 ± 0.5*^b^ | 3.5 ± 0.2
Female Mice
Total Spleen Cells (×10^7^) | 17.40 ± 0.82^▲▲^ | 16.13 ± 0.70 | 14.48 ± 0.45** | 14.77 ± 0.70 | 15.12 ± 1.04 | 14.75 ± 0.65 | 14.9 ± 0.75
Ig+
Absolute | 112.5 ± 4.3^▲▲^ | 92.4 ± 4.0** | 85.4 ± 3.4** | 107.6 ± 4.8 | 100.6 ± 5.9 | 99.2 ± 5.0 | 101.9 ± 5.3
Percent | 65.0 ± 1.8^▲^ | 58.0 ± 3.2 | 59.1 ± 2.0 | 72.9 ± 1.0^▲^ | 67.0 ± 2.3 | 67.4 ± 2.5 | 68.0 ± 1.0*
CD3+
Absolute | 28.2 ± 1.7 | 22.5 ± 1.1* | 23.1 ± 1.2 | 20.2 ± 1.4 | 18.7 ± 2.2 | 20.5 ± 1.7 | 19.6 ± 2.1
Percent | 16.3 ± 1.0 | 14.1 ± 0.9 | 16.0 ± 0.8 | 13.6 ± 0.5 | 12.2 ± 0.7 | 13.8 ± 0.6 | 12.9 ± 0.9
CD4+CD8−
Absolute | 18.4 ± 1.2 | 15.5 ± 0.8 | 15.8 ± 0.8 | 13.6 ± 0.9 | 12.3 ± 1.9 | 13.5 ± 1.3 | 11.8 ± 1.3
Percent | 10.6 ± 0.6 | 9.7 ± 0.5 | 10.9 ± 0.6 | 9.1 ± 0.2 | 7.9 ± 0.8 | 9.1 ± 0.6 | 7.8 ± 0.6
CD4−CD8+
Absolute | 7.1 ± 0.4 | 6.4 ± 0.2 | 6.1 ± 0.5 | 6.2 ± 0.3^▲▲^ | 5.4 ± 0.8 | 4.8 ± 0.5 | 3.5 ± 0.4**
Percent | 4.1 ± 0.3 | 4.0 ± 0.2 | 4.2 ± 0.3 | 4.2 ± 0.1^▲▲^ | 3.5 ± 0.3 | 3.3 ± 0.3* | 2.4 ± 0.2**
CD4+CD8+
Absolute | 0.1 ± 0.0 | 0.1 ± 0.0 | 0.0 ± 0.0 | 0.0 ± 0.0 | 0.0 ± 0.0 | 0.1 ± 0.0 | 0.0 ± 0.0
Percent | 0.0 ± 0.0 | 0.0 ± 0.0 | 0.0 ± 0.0 | 0.0 ± 0.0 | 0.0 ± 0.0 | 0.1 ± 0.0 | 0.0 ± 0.0
NK1.1+CD3−
Absolute | 2.3 ± 0.2^▲^ | 2.2 ± 0.2 | 1.9 ± 0.1 | 1.9 ± 0.1 | 1.8 ± 0.1 | 2.2 ± 0.2 | 1.9 ± 0.2
Percent | 1.4 ± 0.1 | 1.4 ± 0.1 | 1.3 ± 0.1 | 1.3 ± 0.0 | 1.2 ± 0.0 | 1.4 ± 0.1 | 1.3 ± 0.1
MAC-3+
Absolute | 8.0 ± 0.3 | 8.2 ± 0.9 | 6.8 ± 0.4 | 7.2 ± 0.4^▲▲^ | 6.8 ± 0.2 | 5.9 ± 0.4* | 5.6 ± 0.5*
Percent | 4.6 ± 0.2 | 5.0 ± 0.5 | 4.7 ± 0.2 | 4.9 ± 0.4^▲▲^ | 4.6 ± 0.3 | 4.0 ± 0.2 | 3.8 ± 0.3*

^▲^Significant trend (p ≤ 0.05) by Jonckheere’s test.

^▲▲^p ≤ 0.01.

* Significantly different (p ≤ 0.05) from the respective control group by Shirley’s or Dunn’s test; **p ≤ 0.01.

^a^ All values are presented as mean ± standard error.

^b^ n = 7.

Table C-2 T-Dependent Antibody Response to Sheep Red Blood Cells in the Spleen of Female Rats and the Spleen and Serum of Female Mice in the Three-month Nose-only Inhalation Studies of Fullerene Nano-C_60_ (50 nm) and Micro-C_60_ (1 μm)^a^

| 50 nm C_60_ 0 mg/m^3^ | 50 nm C_60_ 0.5 mg/m^3^ | 50 nm C_60_ 2 mg/m^3^ | 1.0 µm C_60_ 0 mg/m^3^ | 1.0 µm C_60_ 2 mg/m^3^ | 1.0 µm C_60_ 15 mg/m^3^ | 1.0 µm C_60_ 30 mg/m^3^
Female Rats
n | 8 | 8 | 8 | 8 | 8 | 8 | 8
Spleen Weight (mg) | 451 ± 19^▲^ | 467 ± 19 | 549 ± 31* | 441 ± 26 | 476 ± 23 | 513 ± 25 | 503 ± 28
Spleen Cells (×10^7^) | 36.93 ± 2.20^▲▲^ | 39.68 ± 2.82 | 53.53 ± 2.30** | 43.00 ± 3.38 | 44.26 ± 2.93 | 42.64 ± 4.37 | 44.13 ± 4.07
IgM PFC/ 10^6^ Spleen Cells | 3,196 ± 635 | 3,038 ± 738 | 3,617 ± 711 | 3,246 ± 750 | 2,838 ± 406 | 4,348 ± 972 | 3,781 ± 697
IgM PFC/ Spleen (×10^3^) | 1,190 ± 274 | 1,241 ± 316 | 1,963 ± 384 | 1,173 ± 34^b^ | 1,231 ± 166 | 1,742 ± 354 | 1,502 ± 187
Female Mice
n | 8 | 8 | 8 | 8 | 8 | 8 | 7
Spleen Weight (mg) | 105 ± 4 | 107 ± 6 | 104 ± 5 | 99 ± 9 | 107 ± 4 | 94 ± 10 | 96 ± 8
Total Spleen Cells (×10^7^) | 17 ± 1 | 17 ± 1 | 17 ± 1 | 18 ± 1 | 19 ± 1 | 17 ± 1 | 20 ± 1
IgM PFC/ 10^6^ Spleen Cells | 1,799 ± 83 | 1,884 ± 159 | 1,978 ± 157 | 1,985 ± 196 | 1,995 ± 84 | 1,934 ± 48 | 1,855 ± 98
IgM PFC/ Spleen (×10^3^) | 305 ± 21 | 330 ± 32 | 340 ± 31 | 359 ± 35 | 382 ± 24 | 336 ± 16 | 369 ± 28
Serum IgM Titer (log2) | 6.79 ± 0.12 | 6.86 ± 0.14 | 6.97 ± 0.11 | 6.91 ± 0.14 | 7.05 ± 0.13 | 6.73 ± 0.10 | 6.93 ± 0.12

^▲^Significant trend (p ≤ 0.01) by Jonckheere’s test.

^▲▲^p ≤ 0.01.

* Significantly different (p ≤ 0.05) from the respective control group by Dunnett’s test; **significantly different (p ≤ 0.01) from the respective control group by Shirley’s test.

PFC = plaque-forming cell.

^a^ All values are presented as mean ± standard error. All endpoints were measured on the day of sacrifice, 4 days following IV administration of sRBCs.

^b^ n =6.

Table C-3 Proliferative Response to Anti-CD3 Antibody in the Spleen of Female Rats and Mice in the Three-month Nose-only Inhalation Studies of Fullerene Nano-C_60_ (50 nm) and Micro-C_60_ (1 μm)^a^

| 50 nm C_60_ 0 mg/m^3^ | 50 nm C_60_ 0.5 mg/m^3^ | 50 nm C_60_ 2 mg/m^3^ | 1.0 µm C_60_ 0 mg/m^3^ | 1.0 µm C_60_ 2 mg/m^3^ | 1.0 µm C_60_ 15 mg/m^3^ | 1.0 µm C_60_ 30 mg/m^3^
n | 8 | 8 | 8 | 8 | 8 | 8 | 8
Female Rats
Total Spleen Cells (×10^7^) | 31.8 ± 2.27 | 31.68 ± 3.45 | 29.57 ± 2.86 | 28.27 ± 1.14 | 31.68 ± 1.75 | 31.46 ± 1.55 | 33.22 ± 2.95
Responders (CPM/2 × 10^5^ spleen cells) | 5,990 ± 829 | 7,062 ± 666 | 8.720 ± 1,157 | 8,018 ± 761 | 9,184 ± 1,078 | 7,440 ± 713 | 8,102 ± 1,670
Responders + Anti-CD3 (CPM/2 × 10^5^ spleen cells) | 77,244 ± 3,931 | 67,462 ± 4,778 | 77,916 ± 5,009 | 72,199 ± 5,041 | 79,720 ± 7,380 | 83,267 ± 4,823 | 80,855 ± 11,144
Mice
Total Spleen Cells (×10^7^) | 17.40 ± 0.82^▲▲^ | 16.13 ± 0.70 | 14.48 ± 0.45** | 14.77 ± 0.70 | 15.12 ± 1.04 | 14.75 ± 0.65 | 14.98 ± 0.75
Responders (CPM/2 × 10^5^ spleen cells) | 166 ± 22^b^ | 167 ± 31 | 173 ± 24 | 203 ± 31 | 108 ± 11* | 155 ± 15 | 166 ± 22
Responders + Anti-CD3 (CPM/2×10^5^ spleen cells) | 37,571 ± 5,458 | 27,635 ± 4,506 | 24,416 ± 5,654 | 30,053 ± 5,922 | 11,958 ± 4,167 | 20,099 ± 4,249 | 24,046 ± 4,023

^▲▲^Significant trend (p ≤ 0.01) by Jonckheere’s test.

* Significantly different (p ≤ 0.05) from the respective control group by Dunn’s test; **significantly different (p ≤ 0.01) from the respective control group by Shirley’s test.

^a^ All values are presented as mean ± standard error.

^b^ n = 7.

Table C-4 Natural Killer Cell Activity in the Spleen of Female Rats and Mice in the Three-month Nose-only Inhalation Studies of Fullerene Nano-C_60_ (50 nm) and Micro-C_60_ (1 µm)^a^

| 50 nm C_60_ 0 mg/m^3^ | 50 nm C_60_ 0.5 mg/m^3^ | 50 nm C_60_ 2 mg/m^3^ | 1.0 µm C_60_ 0 mg/m^3^ | 1.0 µm C_60_ 2 mg/m^3^ | 1.0 µm C_60_ 15 mg/m^3^ | 1.0 µm C_60_ 30 mg/m^3^
n | 8 | 8 | 8 | 8 | 8 | 8 | 8
Female Rats
Spleen Weight (mg) | 429 ± 20 | 446 ± 22 | 410 ± 28 | 426 ± 16 | 406 ± 16 | 388 ± 12 | 430 ± 19
%CYT (200 E:T ratio)^b^ | 23.5 ± 2.4 | 23.6 ± 2.8 | 25.1 ± 1.7 | 24.3 ± 2.9 | 19.7 ± 2.5 | 23.7 ± 2.0 | 25.0 ± 0.7
%CYT (100 E:T ratio) | 18.8 ± 2.8 | 22.8 ± 3.9 | 22.2 ± 2.3 | 16.5 ± 2.3 | 12.1 ± 2.1 | 15.7 ± 2.0 | 16.4 ± 1.1
%CYT (50 E:T ratio) | 9.2 ± 1.8 | 12.8 ± 3.0 | 11.5 ± 1.6 | 9.5 ± 1.8 | 6.2 ± 1.3 | 8.9 ± 1.7 | 8.7 ± 1.3
%CYT (25 E:T ratio) | 4.5 ± 1.6 | 6.4 ± 2.2 | 5.4 ± 1.5 | 3.1 ± 1.5 | 1.1 ± 1.1 | 3.1 ± 1.1 | 3.7 ± 0.8
%CYT (12.5 E:T ratio) | −1.3 ± 1.1 | 0.9 ± 1.7 | 0.5 ± 1.0 | 1.2 ± 1.3 | −0.5 ± 0.8 | 0.6 ± 0.9 | 1.1 ± 0.7
%CYT (6.25 E:T ratio) | −4.8 ± 0.7 | −3.7 ± 1.0 | −3.7 ± 0.7 | −2.5 ± 0.7 | −4.0 ± 0.6 | −2.9 ± 0.7 | −2.5 ± 0.7
Female Mice
Spleen Weight (mg) | 84 ± 5 | 69 ± 8 | 86 ± 6 | 73 ± 5^▲^ | 84 ± 3 | 87 ± 6 | 88 ± 4
%CYT (200 E:T ratio) | 9.9 ± 1.7 | 10.1 ± 2.0 | 6.4 ± 1.5 | 8.6 ± 1.6 | 4.2 ± 1.8 | 7.8 ± 1.9 | 6.9 ± 1.7
%CYT (100 E:T ratio) | 6.6 ± 1.2 | 5.0 ± 1.5 | 4.1 ± 1.3 | 5.1 ± 1.5 | 1.0 ± 1.7 | 3.7 ± 1.4 | 3.8 ± 0.8
%CYT (50 E:T ratio) | 3.1 ± 0.9 | 3.2 ± 0.8 | 1.9 ± 0.7 | 1.8 ± 0.7 | 0.7 ± 0.8 | 2.6 ± 0.9 | 1.7 ± 0.6
%CYT (25 E:T ratio) | 1.2 ± 0.6 | 1.0 ± 0.6 | 0.2 ± 0.5 | 1.1 ± 0.6 | 0.2 ± 0.3 | 1.2 ± 0.5 | 0.9 ± 0.5
%CYT (12.5 E:T ratio) | −0.9 ± 1.0 | −1.0 ± 1.0 | −1.2 ± 0.8 | −0.6 ± 1.1 | −2.8 ± 1.3 | 0.3 ± 0.5 | 0.4 ± 0.5
%CYT (6.25 E:T ratio) | −0.4 ± 0.3 | −0.7 ± 0.3 | −0.7 ± 0.3 | 0.1 ± 0.4 | −0.4 ± 0.4 | −0.1 ± 0.3 | 0.1 ± 0.4

^▲^Significant trend (p ≤ 0.05) by Jonckheere’s test.

^a^ All values are presented as mean ± standard error.

^b^ Effector-to-target-cell ratio.

Table C-5 Mixed Leukocyte Response to DBA/2 Mouse Spleen Cells in Female Mice in the Three-month Nose-only Inhalation Studies of Fullerene Nano-C_60_ (50 nm) and Micro-C_60_ (1 µm)^a^

| 50 nm C_60_ 0 mg/m^3^ | 50 nm C_60_ 0.5 mg/m^3^ | 50 nm C_60_ 2 mg/m^3^ | 1.0 µm C_60_ 0 mg/m^3^ | 1.0 µm C_60_ 2 mg/m^3^ | 1.0 µm C_60_ 15 mg/m^3^ | 1.0 µm C_60_ 30 mg/m^3^
n | 8 | 8 | 8 | 8 | 8 | 8 | 8
Total Spleen Cells (×10^7^) | 17.40 ± 0.82^▲▲^ | 16.13 ± 0.70 | 14.48 ± 0.45** | 14.77 ± 0.70 | 15.12 ± 1.04 | 14.75 ± 0.65 | 14.98 ± 0.75
Responders (CPM/10^5^ spleen cells) | 545 ± 145 | 388 ± 63 | 358 ± 76 | 440 ± 65 | 314 ± 62 | 426 ± 56 | 278 ± 32
Responders + Stimulators (CPM/10^5^ spleen cells) | 30,692 ± 4,731 | 33,844 ± 4,974 | 23,124 ± 5,550 | 56,399 ± 13,062 | 18,271 ± 5,240* | 28,889 ± 4,600 | 28,460 ± 6,736

^▲▲^Significant trend (p ≤ 0.01) by Jonckheere’s test.

* Significantly different (p ≤ 0.05) from the respective control group by Dunn’s test; **significantly different (p ≤ 0.01) from the respective control group by Shirley’s test.

^a^ All values are presented as mean ± standard error.

Table C-6 Bronchoalveolar Lavage Cell Phenotypes of Female Rats in the Three-month Nose-only Inhalation Studies of Fullerene Nano-C_60_ (50 nm) and Micro-C_60_ (1 µm)^a^

| 50 nm C_60_ 0 mg/m^3^ | 50 nm C_60_ 0.5 mg/m^3^ | 50 nm C_60_ 2 mg/m^3^ | 1.0 µm C_60_ 0 mg/m^3^ | 1.0 µm C_60_ 2 mg/m^3^ | 1.0 µm C_60_ 15 mg/m^3^ | 1.0 µm C_60_ 30 mg/m^3^
n | 8 | 8 | 8 | 8 | 8 | 8 | 8
BAL Cells (×10^5^) | 10.77 ± 0.71 | 10.30 ± 0.72 | 9.80 ± 0.65 | 10.18 ± 0.71 | 9.90 ± 0.85 | 9.78 ± 1.12 | 14.92 ± 1.92
CD163+CD11b−
Absolute | 0.42 ± 0.09 | 0.53 ± 0.19 | 0.22 ± 0.06 | 0.47 ± 0.24 | 0.13 ± 0.02 | 0.21 ± 0.08 | 0.28 ± 0.06
Percent | 0.38 ± 0.07 | 0.54 ± 0.18 | 0.24 ± 0.06 | 0.42 ± 0.20 | 0.13 ± 0.02 | 0.20 ± 0.07 | 0.23 ± 0.07
CD163+CD11b+
Absolute | 13.54 ± 3.76^▲▲^ | 1.87 ± 0.88** | 1.16 ± 0.48** | 19.36 ± 8.71^▲^ | 0.38 ± 0.11** | 0.35 ± 0.14** | 1.07 ± 0.34
Percent | 12.37 ± 3.06^▲▲^ | 1.79 ± 0.76** | 1.34 ± 0.63** | 17.25 ± 7.12^▲▲^ | 0.37 ± 0.09** | 0.32 ± 0.12** | 0.88 ± 0.31**
CD163−CD11b−
Absolute | 92.60 ± 6.54 | 95.77 ± 6.87 | 92.88 ± 7.85 | 80.39 ± 7.93^▲^ | 97.45 ± 8.34 | 96.54 ± 10.93 | 137.2 ± 20.23*
Percent | 86.17 ± 3.39^▲^ | 93.27 ± 3.02 | 94.07 ± 3.44 | 80.93 ± 7.64 | 98.50 ± 0.53** | 98.79 ± 0.31** | 90.52 ± 2.88
CD163−CD11b+
Absolute | 1.14 ± 0.28 | 4.82 ± 2.64 | 3.74 ± 2.13 | 1.59 ± 0.54^▲▲^ | 1.04 ± 0.54 | 0.72 ± 0.20 | 10.62 ± 2.85**
Percent | 1.08 ± 0.29 | 4.40 ± 2.13 | 4.36 ± 2.77 | 1.40 ± 0.42^▲^ | 0.99 ± 0.45 | 0.69 ± 0.16 | 8.37 ± 2.53*

^▲^Significant trend (p ≤ 0.05) by Jonckheere’s test.

^▲▲^p ≤ 0.01.

* Significantly different (p ≤ 0.05) from the respective control group by Shirley’s or Dunn’s test; **p ≤ 0.01.

^a^ All values are presented as mean ± standard error. BAL = bronchoalveolar lavage.

Table C-7 Cytokine Levels in the Bronchoalveolar Lavage Fluid of Female Rats and Mice in the Three-month Nose-only Inhalation Studies of Fullerene Nano-C_60_ (50 nm) and Micro-C_60_ (1 μm)^a^

| 50 nm C_60_ 0 mg/m^3^ | 50 nm C_60_ 0.5 mg/m^3^ | 50 nm C_60_ 2 mg/m^3^ | 1.0 µm C_60_ 0 mg/m^3^ | 1.0 µm C_60_ 2 mg/m^3^ | 1.0 µm C_60_ 15 mg/m^3^ | 1.0 µm C_60_ 30 mg/m^3^
n | 8 | 8 | 8 | 8 | 8 | 8 | 8
Female Rats
IL-1 (pg/mL)
Neat | 15.09 ± 7.89 | 17.18 ± 9.04 | 0.00 ± 0.00 | 35.88 ± 8.59 | 10.00 ± 6.56 | 11.50 ± 8.32 | 16.9 ± 7.23
Concentrated | 17.86 ± 8.69 | 16.79 ± 8.35 | 2.83 ± 2.83 | 4.35 ± 4.35^▲▲^ | 26.97 ± 12.37 | 35.28 ± 8.80* | 73.72 ± 13.74**
MCP-1 (pg/mL)
Neat | 5.67 ± 2.56 | 4.24 ± 1.93 | 2.18 ± 1.49 | 13.70 ± 2.44 | 4.24 ± 1.99 | 4.00 ± 2.74 | 89.09 ± 31.32
Concentrated | 93.41 ± 23.95 | 66.05 ± 13.36 | 74.88 ± 19.01 | 65.44 ± 21.71^▲▲^ | 47.95 ± 7.01 | 68.64 ± 13.90 | 622.4 ± 146.8**
TNF-α (pg/mL)
Neat | 4.56 ± 3.05 | 2.42 ± 2.42 | 0.00 ± 0.00 | 21.89 ± 5.21^▲^ | 6.50 ± 4.44 | 4.37 ± 4.37* | 4.28 ± 2.80*
Concentrated | 11.25 ± 3.45^▲^ | 8.29 ± 4.23 | 0.00 ± 0.00* | 4.71 ± 3.14 | 12.51 ± 6.72 | 14.70 ± 5.17 | 8.68 ± 4.30
IFN-γ (pg/mL)
Neat | 0.00 ± 0.00 | 0.00 ± 0.00 | 0.00 ± 0.00 | 0.00 ± 0.00 | 0.00 ± 0.00 | 0.00 ± 0.00 | 0.00 ± 0.00
Concentrated | 0.00 ± 0.00 | 0.00 ± 0.00 | 0.00 ± 0.00 | 0.00 ± 0.00 | 0.00 ± 0.00 | 0.00 ± 0.00 | 0.00 ± 0.00
GM-CSF (pg/mL)
Neat | 22.10 ± 11.11 | 28.40 ± 11.11 | 0.00 ± 0.00 | 53.60 ± 12.62 | 16.97 ± 11.14 | 10.00 ± 10.00* | 21.68 ± 10.62
Concentrated | 36.56 ± 11.35^▲^ | 21.75 ± 10.82 | 5.66 ± 5.66 | 12.80 ± 8.45 | 38.30 ± 15.56 | 42.58 ± 10.33 | 26.90 ± 13.49
IL-4
Neat | 0.19 ± 0.14 | 0.10 ± 0.10 | 0.00 ± 0.00 | 0.79 ± 0.31^▲^ | 0.10 ± 0.10 | 0.20 ± 0.20 | 0.05 ± 0.05*
Concentrated | 0.00 ± 0.00 | 0.00 ± 0.00 | 0.00 ± 0.00 | 0.00 ± 0.00 | 0.21 ± 0.21 | 0.00 ± 0.00 | 0.00 ± 0.00
Female Mice
IL-13 (pg/mL)
Neat | 45.38 ± 5.89 | 35.67 ± 4.64 | 50.68 ± 5.29 | 35.61 ± 3.94 | 49.11 ± 4.77 | 33.84 ± 3.78 | 39.69 ± 7.41
Concentrated | 77.41 ± 17.23 | 74.28 ± 9.63 | 48.29 ± 7.68 | 37.90 ± 9.18 | 47.7 ± 8.93 | 46.51 ± 4.95 | 51.75 ± 11.02
IL-1 (pg/mL)
Neat | 79.04 ± 12.18 | 68.83 ± 10.14 | 85.32 ± 7.81 | 52.60 ± 8.69 | 86.96 ± 12.47 | 62.73 ± 9.96 | 68.73 ± 16.05
Concentrated | 138.5 ± 16.37 | 141.2 ± 8.28 | 108.2 ± 16.22 | 99.89 ± 11.97 | 111.5 ± 8.56 | 111.4 ± 4.90 | 106.5 ± 17.37
IL-2 (pg/mL)
Neat | 187.5 ± 14.66 | 151.4 ± 9.67 | 180.0 ± 17.76 | 149.8 ± 13.96 | 196.5 ± 19.50 | 137.7 ± 19.12 | 164.1 ± 29.50
Concentrated | 233.7 ± 24.62 | 235.4 ± 10.91 | 183.0 ± 27.17 | 186.8 ± 18.67 | 201.3 ± 12.46 | 201.4 ± 9.48 | 204.7 ± 22.67
IL-5 (pg/mL)
Neat | 119.5 ± 19.56 | 106.9 ± .13.64 | 119.5 ± 15.42 | 86.97 ± 14.80 | 129.9 ± 17.21 | 102.0 ± 15.73 | 104.7 ± 22.74
Concentrated | 222.2 ± 26.73 | 224.7 ± 13.64 | 167.7 ± 25.58 | 152.5 ± 18.28 | 183.6 ± 13.96 | 181.8 ± 11.01 | 172.6 ± 27.86
MCP-1 (pg/mL)
Neat | 429.7 ± 82.27 | 253.7 ± 68.57 | 388.7 ± 75.37 | 345.2 ± 69.45 | 531.3 ± 89.76 | 283.2 ± 70.15 | 507.3 ± 97.61
Concentrated | 1,096 ± 152.1 | 1,171 ± 59.37 | 846.3 ± 125.7 | 861.0 ± 86.15 | 959.0 ± 88.24 | 902.9 ± 44.02 | 1,223 ± 142.9
IL-6 (pg/mL)
Neat | 16.30 ± 5.60 | 7.23 ± 4.51 | 18.25 ± 6.83 | 8.50 ± 4.84 | 21.36 ± 6.88 | 4.93 ± 2.64 | 19.13 ± 6.08
Concentrated | 68.62 ± 7.93^▲^ | 68.89 ± 4.59 | 52.70 ± 4.61 | 50.91 ± 4.08 | 55.97 ± 4.40 | 55.57 ± 2.22 | 60.56 ± 6.04
MIP-1α (pg/mL)
Neat | 0.18 ± 0.18 | 0.0 ± 0.0 | 2.06 ± 1.37 | 0.0 ± 0.0^▲▲^ | 0.65 ± 0.65 | 2.36 ± 0.95** | 94.09 ± 12.25**
Concentrated | 6.76 ± 3.28 | 6.17 ± 1.79 | 11.89 ± 2.84 | 0.74 ± 0.74^▲▲^ | 1.95 ± 1.13 | 23.12 ± 3.16** | 236.6 ± 38.38**
IL-10 (pg/mL)
Neat | 32.37 ± 9.88 | 9.91 ± 9.91 | 21.83 ± 9.04 | 27.45 ± 9.32 | 53.53 ± 18.89 | 10.02 ± 3.80 | 42.86 ± 11.87
Concentrated | 130.8 ± 25.95 | 122.3 ± 16.79 | 79.04 ± 12.85 | 62.00 ± 11.64 | 77.01 ± 14.03 | 84.70 ± 8.97 | 91.78 ± 18.51
RANTES (pg/mL)
Neat | 35.99 ± 12.15 | 14.64 ± 12.00 | 41.43 ± 12.01 | 12.76 ± 9.72 | 46.85 ± 15.51 | 9.65 ± 4.52 | 42.03 ± 13.15
Concentrated | 78.07 ± 21.26 | 74.14 ± 12.82 | 39.05 ± 5.94 | 26.58 ± 8.72 | 31.54 ± 9.36 | 32.25 ± 6.79 | 47.54 ± 12.60
IFN-γ (pg/mL)
Neat | 34.00 ± 10.17 | 19.72 ± 7.25 | 36.39 ± 9.59 | 15.01 ± 7.81 | 42.16 ± 14.22 | 15.4 ± 3.70 | 35.17 ± 9.08
Concentrated | 98.55 ± 19.47 | 90.58 ± 10.29 | 59.32 ± 9.26 | 45.30 ± 9.45 | 62.23 ± 8.24 | 59.81 ± 4.36 | 67.26 ± 14.59
TNF-α (pg/mL)
Neat | 16.46 ± 6.77 | 5.75 ± 5.75 | 15.18 ± 6.94 | 7.68 ± 4.74 | 20.86 ± 7.67 | 3.26 ± 2.00 | 20.14 ± 5.93
Concentrated | 55.24 ± 14.23 | 53.74 ± 6.73 | 30.26 ± 4.53 | 25.29 ± 3.96 | 31.46 ± 4.00 | 29.15 ± 1.74 | 38.04 ± 8.32
GM-CSF (pg/mL)
Neat | 109.2 ± 18.14 | 95.19 ± 11.29 | 137.9 ± 12.91 | 90.46 ± 17.38 | 133.8 ± 16.50 | 79.47 ± 12.36 | 107.7 ± 24.82
Concentrated | 194.3 ± 22.56 | 193.8 ± 11.31 | 144.3 ± 21.27 | 145.2 ± 12.26 | 158.5 ± 11.68 | 159.2 ± 4.25 | 153.4 ± 24.56
IL-4
Neat | 21.78 ± 8.10 | 10.20 ± 7.89 | 26.36 ± 11.50 | 14.91 ± 7.29 | 42.06 ± 15.07 | 6.83 ± 3.59 | 35.06 ± 10.51
Concentrated | 102.1 ± 21.65 | 98.18 ± 13.09 | 60.20 ± 10.76 | 49.82 ± 10.60 | 59.47 ± 11.67 | 57.64 ± 5.44 | 63.33 ± 14.39
IL-17 (pg/mL)
Neat | 3.35 ± 3.21 | 2.40 ± 2.40 | 8.10 ± 5.73 | 3.80 ± 3.80 | 14.87 ± 8.21 | 0.00 ± 0.00 | 12.73 ± 4.01
Concentrated | 43.89 ± 14.20 | 44.08 ± 8.66 | 22.09 ± 5.37 | 12.60 ± 5.37 | 20.88 ± 6.39 | 19.04 ± 4.29 | 27.52 ± 9.54

^▲^Significant trend (p ≤ 0.05) by Jonckheere’s test.

^▲▲^p ≤ 0.01.

* Significantly different (p ≤ 0.05) from the respective control group by Shirley’s or Dunn’s test; **p ≤ 0.01.

^a^ All values are presented as mean ± standard error.