# Appendix B Tissue Burden Results

## B.1 Lung Deposition and Clearance Equations Used in the Three-month Nose-only Inhalation Studies of Fullerene C_60_ (1 µm and 50 nm)

Lung burdens at t = 0 days postexposure and lung clearance rates were determined using the clearance model shown in Equation (1):

Equation (1): A(t) = A_0_(e^−kt^)

where A(t) is the lung burden (µg fullerene C_60_) at each postexposure time point t (t = days postexposure), A_0_ is the lung burden at t = 0 days postexposure, and k is the lung clearance rate constant (fraction cleared per day [day^−1^]).

Lung clearance half-lives in days (t_1/2_) were calculated from Equation (2):

Equation (2): t_1/2_ = ln2/k

Deposition rates were calculated from lung burdens using Equation (3). The lung burden and time at terminal kill and the calculated lung clearance rate constant were used to solve for the deposition rate α (µg/day).

Equation (3): A(t) = (α/k)(1 – e^−kt^)

In Equation (3), A(t) is the lung burden (µg fullerene C_60_) at time t; α is the amount of fullerene C_60_ deposited (µg/day); and k is the first-order clearance rate constant derived from Equation (1). Steady-state or equilibrium lung burdens (A_e_, µg fullerene C_60_) were calculated according to Equation (4):

Equation (4): A_e_ = α/k

## B.2 Results for Rats

Table B-1 Tissue Weights, Fullerene C_60_ Concentrations, and Fullerene C_60_ Burdens for Rats in the Three-month Nose-only Inhalation Study of Fullerene Micro-C_60_ (1 µm)^a^

| 0 mg/m^3^ | 2 mg/m^3^ | 15 mg/m^3^ | 30 mg/m^3^
Male
n | 6 | 6 | 6 | 6
Bronchial Lymph Node
Absolute bronchial lymph node wt. (g)
Day 88 | 0.030 ± 0.005 | 0.029 ± 0.006 | 0.031 ± 0.002 | 0.051 ± 0.005*
µg Fullerene C_60_/g bronchial lymph node
Day 88 | 0.526 ± 0.097^b^ | 1.889 ± 0.544**^b^ | 82.661 ± 49.095** | 1,188.098 ± 421.212**^b^
µg Fullerene C_60_/total bronchial lymph node
Day 88 | 0.014 ± 0.001^b^ | 0.045 ± 0.011^b^ | 2.704 ± 1.641** | 61.886 ± 22.164**^b^
µg Fullerene C_60_/total bronchial lymph node per mg fullerene C_60_/m^3^
Day 88 | NA | 0.023 ± 0.005^b^ | 0.180 ± 0.109 | 2.063 ± 0.739^b^
Spleen
Absolute spleen wt. (g)
Day 88 | 0.624 ± 0.031 | 0.561 ± 0.023 | 0.632 ± 0.051 | 0.566 ± 0.026
µg Fullerene C_60_/g spleen
Day 88 | 0.003 ± 0.000^c^ | 0.011 ± 0.009^c^ | 0.026 ± 0.011 | 0.046 ± 0.017*^c^
µg Fullerene C_60_/total spleen
Day 88 | 0.002 ± 0.000^b^ | 0.006 ± 0.004^c^ | 0.018 ± 0.008 | 0.027 ± 0.010^c^
µg Fullerene C_60_/total spleen per mg fullerene C_60_/m^3^
Day 88 | NA | 0.003 ± 0.02^c^ | 0.001 ± 0.001 | 0.001 ± 0.000^c^
Liver
Absolute liver wt. (g)
Day 88 | 12.507 ± 0.496 | 11.639 ± 0.431 | 11.886 ± 0.261 | 10.426 ± 0.387**
µg Fullerene C_60_/g liver
Day 88 | 0.004 ± 0.000^b^ | 0.004 ± 0.000^b^ | 0.007 ± 0.002 | 0.015 ± 0.006**^b^
µg Fullerene C_60_/total liver
Day 88 | 0.050 ± 0.002^b^ | 0.047 ± 0.002^b^ | 0.088 ± 0.031 | 0.161 ± 0.066^b^
µg Fullerene C_60_/total liver per mg fullerene C_60_/m^3^
Day 88 | NA | 0.023 ± 0.01^b^ | 0.006 ± 0.002 | 0.005 ± 0.002^b^
Lung
Absolute lung wt. (g)
Day 88 | 1.413 ± 0.093 | 1.229 ± 0.049 | 1.281 ± 0.053 | 1.221 ± 0.044
PE Day 14 | 1.483 ± 0.060 | 1.552 ± 0.091 | 1.631 ± 0.114 | 2.012 ± 0.210**
PE Day 28 | 1.639 ± 0.160 | 1.746 ± 0.096 | 1.661 ± 0.100 | 1.728 ± 0.188
PE Day 56 | 1.437 ± 0.067 | 1.591 ± 0.102 | 1.712 ± 0.039** | 1.694 ± 0.040**
µg Fullerene C_60_/g lung
Day 88 | 0.122 ± 0.027^b^ | 358.103 ± 19.667**^b^ | 1,681.645 ± 233.880** | 4,659.764 ± 344.713**^b^
PE Day 14 | 0.025 ± 0.010 | 157.113 ± 17.980** | 901.140 ± 103.671** | 2,796.07 ± 315.546**
PE Day 28 | 0.027 ± 0.012 | 128.255 ± 15.397** | 1,088.54 ± 223.310** | 2,388.87 ± 291.212**
PE Day 56 | 0.042 ± 0.018^b^ | 73.285 ± 11.566**^b^ | 669.586 ± 138.945** | 1,660.43 ± 198.512**^b^
µg Fullerene C_60_/total lung
Day 88 | 0.181 ± 0.046^b^ | 438.806 ± 26.973**^b^ | 2,182.396 ± 358.886** | 5,748.744 ± 582.344**^b^
PE Day 14 | 0.039 ± 0.018 | 242.932 ± 27.575** | 1,419.92 ± 127.344** | 5,521.69 ± 633.566**
PE Day 28 | 0.044 ± 0.019 | 228.353 ± 36.470** | 1,754.34 ± 337.908** | 4,084.52 ± 556.664**
PE Day 56 | 0.057 ± 0.024^b^ | 109.333 ± 14.820**^b^ | 1,150.20 ± 238.847** | 2,879.47 ± 371.692**^b^
µg Fullerene C_60_/total lung per mg fullerene C_60_/m^3^
Day 88 | NA | 219.4 ± 13.56^b^ | 145.5 ± 23.96 | 191.6 ± 19.41^b^
PE Day 14 | NA | 121.466 ± 13.787 | 94.661 ± 8.490 | 184.056 ± 21.119
PE Day 28 | NA | 114.176 ± 18.235 | 116.956 ± 22.527 | 136.151 ± 18.555
PE Day 56 | NA | 54.667 ± 7.410^b^ | 76.680 ± 15.923 | 95.982 ± 12.390^b^
Female
n | 8 | 8 | 8 | 8
Bronchial Lymph Node
Absolute bronchial lymph node wt. (g)
Day 88 | 0.021 ± 0.002 | 0.020 ± 0.001 | 0.023 ± 0.003 | 0.030 ± 0.002
µg Fullerene C_60_/g bronchial lymph node
Day 88 | 0.602 ± 0.028^d^ | 2.844 ± 0.389**^d^ | 53.488 ± 13.325** | 1,766.176 ± 391.460**^d^
µg Fullerence-C_60_/total bronchial lymph node
Day 88 | 0.013 ± 0.001^d^ | 0.056 ± 0.010**^d^ | 1.012 ± 0.187** | 54.527 ± 12.944**^d^
µg Fullerene C_60_/total lymph node per mg fullerene C_60_/m^3^
Day 88 | NA | 0.028 ± 0.005^d^ | 0.067 ± 0.012 | 1.821 ± 0.431^d^
Spleen
Absolute spleen wt. (g)
Day 88 | 0.415 ± 0.012 | 0.416 ± 0.021 | 0.405 ± 0.026 | 0.388 ± 0.011
µg Fullerene C_60_/g spleen
Day 88 | 0.003 ± 0.000^e^ | 0.003 ± 0.000^e^ | 0.003 ± 0.000 | 0.136 ± 0.118^d^
µg Fullerene C_60_/total spleen
Day 88 | 0.001 ± 0.000^e^ | 0.001 ± 0.000^e^ | 0.001 ± 0.000 | 0.056 ± 0.048^d^
µg Fullerene C_60_/total spleen per mg fullerene C_60_/m^3^
Day 88 | NA | 0.001 ± 0.000^e^ | 0.000 ± 0.000 | 0.002 ± 0.002^d^
Liver
Absolute liver wt. (g)
Day 88 | 7.205 ± 0.290 | 6.448 ± 0.271 | 6.510 ± 0.307 | 6.161 ± 0.310
µg Fullerene C_60_/g liver
Day 88 | 0.004 ± 0.000^d^ | 0.004 ± 0.000^d^ | 0.008 ± 0.003 | 0.007 ± 0.002^d^
µg Fullerene C_60_/total liver
Day 88 | 0.029 ± 0.001^d^ | 0.026 ± 0.001^d^ | 0.050 ± 0.018 | 0.045 ± 0.010^d^
µg Fullerene C_60_/total liver per mg fullerene C_60_/m^3^
Day 88 | NA | 0.013 ± 0.001^d^ | 0.003 ± 0.001 | 0.001 ± 0.000^d^
Lung
Absolute lung wt. (g)
Day 88 | 0.919 ± 0.030 | 0.936 ± 0.033 | 0.997 ± 0.052 | 0.978 ± 0.034
µg Fullerene C_60_/g lung
Day 88 | 0.259 ± 0.026^d^ | 252.037 ± 13.281**^d^ | 1,769.746 ± 84.185** | 4,706.482 ± 230.457**^d^
µg Fullerene C_60_/total lung
Day 88 | 0.239 ± 0.026^d^ | 234.274 ± 13.648**^d^ | 1,763.436 ± 126.305** | 4,657.878 ± 372.741**^d^
µg Fullerene C_60_/total lung per mg fullerene C_60_/m^3^
Day 88 | NA | 117.137 ± 6.824^d^ | 117.562 ± 8.420 | 115.263 ± 12.425^d^

* Significantly different (p ≤ 0.05) from the control group by Shirley’s test; **p ≤ 0.01.

^a^ Data are presented as mean ± standard error. Statistical tests were not performed on data that were normalized to fullerene C_60_ exposure concentration. NA = not applicable; PE = postexposure.

^b^ n = 5.

^c^ n = 4.

^d^ n = 7.

^e^ n = 6.

Table B-2 Lung Deposition and Clearance Parameter Estimates for Male Rats in the Three-month Nose-only Inhalation Study of Fullerene Micro-C_60_ (1 µm)^a^

Parameter | 2 mg/m^3^ | 15 mg/m^3^ | 30 mg/m^3^
A_0_ (µg fullerene C_60_/total lung) | 416 | 2,037 | 6,032
k (days^−1^) | 0.026 | 0.010 | 0.013
t_1/2_ (days) | 27 | 69 | 55
α (µg fullerene C_60_/total lung per day) | 12 | 35 | 113
A_e_ (µg fullerene C_60_/total lung) | 465 | 3,472 | 9,010

A_0_=lung burden at t = 0 days postexposure; k = first-order lung clearance rate constant; t_1/2_=lung clearance half-life; α = lung deposition rate; A_e_=steady-state lung burden.

^a^ Data are presented as mean values.

Table B-3 Tissue Weights, Fullerene C_60_ Concentrations, and Fullerene C_60_ Burdens for Rats in the Three-month Nose-only Inhalation Study of Fullerene Nano-C_60_ (50 nm)^a^

| 0 mg/m^3^ | 0.5 mg/m^3^ | 2 mg/m^3^
Male
n | 6 | 6 | 6
Bronchial Lymph Node
Absolute bronchial lymph node wt. (g)
Day 89 | 0.032 ± 0.004 | 0.033 ± 0.002 | 0.041 ± 0.003
µg Fullerene C_60_/g bronchial lymph node
Day 89 | 0.617 ± 0.161^b^ | 0.734 ± 0.059^b^ | 2.332 ± 0.461**^b^
µg Fullerene C_60_/total bronchial lymph node
Day 89 | 0.016 ± 0.002^b^ | 0.025 ± 0.002**^b^ | 0.095 ± 0.018**^b^
µg Fullerene C_60_/total bronchial lymph node per mg fullerene C_60_/m^3^
Day 89 | NA | 0.050 ± 0.003^b^ | 0.047 ± 0.009^b^
Spleen
Absolute spleen wt. (g)
Day 89 | 0.531 ± 0.041 | 0.544 ± 0.025 | 0.509 ± 0.025
µg Fullerene C_60_/g spleen
Day 89 | 0.003 ± 0.000^c^ | 0.003 ± 0.00^c^ | 0.022 ± 0.014^c^
µg Fullerene C_60_/total spleen
Day 89 | 0.001 ± 0.000^c^ | 0.001 ± 0.000^c^ | 0.012 ± 0.008^c^
µg Fullerene C_60_/total spleen per mg fullerene C_60_/m^3^
Day 89 | NA | 0.003 ± 0.000^c^ | 0.006 ± 0.004^c^
Liver
Absolute liver wt. (g)
Day 89 | 10.641 ± 0.584 | 10.011 ± 0.298 | 9.948 ± 0.278
µg Fullerene C_60_/g liver
Day 89 | 0.004 ± 0.000^b^ | 0.004 ± 0.000^b^ | 0.006 ± 0.001^b^
µg Fullerene C_60_/total liver
Day 89 | 0.042 ± 0.003^b^ | 0.040 ± 0.001^b^ | 0.058 ± 0.012^b^
µg Fullerene C_60_/total liver per mg fullerene C_60_/m^3^
Day 89 | NA | 0.080 ± 0.003^b^ | 0.029 ± 0.006^b^
Lung
Absolute lung wt. (g)
Day 89 | 1.447 ± 0.101 | 1.424 ± 0.064 | 1.404 ± 0.077
PE Day 14 | 1.489 ± 0.103 | 1.797 ± 0.083 | 1.776 ± 0.102
PE Day 28 | 1.517 ± 0.110 | 2.113 ± 0.161** | 1.629 ± 0.067
PE Day 56 | 1.649 ± 0.139 | 1.645 ± 0.027 | 1.846 ± 0.074*
µg Fullerene C_60_/g lung
Day 89 | 0.069 ± 0.031^b^ | 103.574 ± 5.358**^b^ | 414.382 ± 33.979**^b^
PE Day 14 | 0.021 ± 0.006 | 68.509 ± 3.173** | 274.966 ± 8.506**
PE Day 28 | 0.115 ± 0.024 | 63.371 ± 7.730** | 334.298 ± 38.944**
PE Day 56 | 0.046 ± 0.020^b^ | 31.973 ± 4.134**^b^ | 141.400 ± 20.492**^b^
µg Fullerene C_60_/total lung
Day 89 | 0.086 ± 0.034^b^ | 189.217 ± 4.928**^b^ | 580.890 ± 45.767**^b^
PE Day 14 | 0.031 ± 0.009 | 122.324 ± 5.302** | 487.523 ± 30.124**
PE Day 28 | 0.176 ± 0.035 | 136.756 ± 24.762** | 538.166 ± 53.556**
PE Day 56 | 0.076 ± 0.032^b^ | 52.629 ± 6.201**^b^ | 248.916 ± 31.078**^b^
µg Fullerene C_60_/total lung per mg fullerene C_60_/m^3^
Day 89 | NA | 378.43 ± 9.86^b^ | 290.45 ± 22.88^b^
PE Day 14 | NA | 244.649 ± 10.60 | 243.761 ± 15.062
PE Day 28 | NA | 273.511 ± 49.523 | 269.083 ± 26.778
PE Day 56 | NA | 105.259 ± 12.403^b^ | 124.458 ± 15.539^b^
Female
n | 8 | 8 | 8
Bronchial Lymph Node
Absolute bronchial lymph node wt. (g)
Day 89 | 0.024 ± 0.002 | 0.028 ± 0.005 | 0.025 ± 0.004
µg Fullerene C_60_/g bronchial lymph node
Day 89 | 0.570 ± 0.044^d^ | 0.860 ± 0.141^d^ | 4.926 ± 1.537**^d^
µg Fullerene C_60_/total bronchial lymph node
Day 89 | 0.014 ± 0.001^d^ | 0.023 ± 0.003*^d^ | 0.100 ± 0.012**^d^
µg Fullerene C_60_/total bronchial lymph node per mg fullerene C_60_/m^3^
Day 89 | NA | 0.046 ± 0.006^d^ | 0.050 ± 0.006^d^
Spleen
Absolute spleen wt. (g)
Day 89 | 0.394 ± 0.018 | 0.422 ± 0.031 | 0.391 ± 0.026
µg Fullerene C_60_/g spleen
Day 89 | 0.003 ± 0.000^e^ | 0.020 ± 0.017^e^ | 0.003 ± 0.000^e^
µg Fullerene C_60_/total spleen
Day 89 | 0.001 ± 0.000^e^ | 0.007 ± 0.006^e^ | 0.001 ± 0.000^e^
µg Fullerene C_60_/total spleen per mg fullerene C_60_/m^3^
Day 89 | NA | 0.015 ± 0.012^e^ | 0.000 ± 0.000^e^
Liver
Absolute liver wt. (g)
Day 89 | 6.259 ± 0.221 | 6.644 ± 0.386 | 6.015 ± 0.277
µg Fullerene C_60_/g liver
Day 89 | 0.005 ± 0.001^d^ | 0.004 ± 0.000^d^ | 0.006 ± 0.001^d^
µg Fullerene C_60_/total liver
Day 89 | 0.034 ± 0.009^d^ | 0.027 ± 0.002^d^ | 0.034 ± 0.006^d^
µg Fullerene C_60_/total liver per mg fullerene C_60_/m^3^
Day 89 | NA | 0.054 ± 0.003^d^ | 0.017 ± 0.003^d^
Lung
Absolute lung wt. (g)
Day 89 | 1.065 ± 0.066 | 1.266 ± 0.077 | 0.971 ± 0.057
µg Fullerene C_60_/g lung
Day 89 | 0.086 ± 0.030^d^ | 102.128 ± 12.142**^d^ | 442.346 ± 33.335**^d^
µg Fullerene C_60_/total lung
Day 89 | 0.088 ± 0.031^d^ | 128.396 ± 9.442**^d^ | 433.868 ± 27.467**^d^
µg Fullerene C_60_/total lung per mg fullerene C_60_/m^3^
Day 89 | NA | 256.792 ± 18.884^d^ | 216.934 ± 13.733^d^

* Significantly different (p ≤ 0.05) from the control group by Dunn’s or Shirley’s test; **p ≤ 0.01.

^a^ Data are presented as mean ± standard error. Statistical tests were not performed on data that were normalized to fullerene C_60_ exposure concentration. NA = not applicable; PE = postexposure.

^b^ n = 5.

^c^ n = 4.

^d^ n = 7.

^e^ n = 6.

Table B-4 Lung Deposition and Clearance Parameter Estimates for Male Rats in the Three-month Nose-only Inhalation Study of Fullerene Nano-C_60_ (50 nm)^a^

Parameter | 0.5 mg/m^3^ | 2 mg/m^3^
A_0_ (µg fullerene C_60_/total lung) | 185 | 604
k (days^−1^) | 0.018 | 0.011
t_1/2_ (days) | 38 | 61
α (µg fullerene C_60_/total lung per day) | 4.2 | 10.8
A_e_ (µg fullerene C_60_/total lung) | 229 | 946

A_0_ = lung burden at t = 0 days postexposure; k = first-order lung clearance rate constant; t_1/2_ = lung clearance half-life; α = lung deposition rate; A_e_ = steady-state lung burden.

^a^ Data are presented as mean values.

## B.3 Results for Mice

Table B-5 Tissue Weights, Fullerene C_60_ Concentrations, and Fullerene C_60_ Burdens for Mice in the Three-month Nose-only Inhalation Study of Fullerene Micro-C_60_ (1 µm)^a^

| 0 mg/m^3^ | | 2 mg/m^3^ | | 15 mg/m^3^ | 30 mg/m^3^
Male
n | 6 | | 6 | | 6 | 6
Bronchial Lymph Node
Absolute bronchial lymph node wt. (g)
Day 88 | 0.012 ± 0.002 | | 0.010 ± 0.001 | | 0.016 ± 0.004 | 0.012 ± 0.003
µg Fullerene C_60_/g bronchial lymph node
Day 88 | 0.718 ± 0.113^b^ | | 1.964 ± 0.136**^b^ | | 142.650 ± 54.106** | 1,692.370 ± 454.458**^b^
µg Fullerene C_60_/total bronchial lymph node
Day 88 | 0.008 ± 0.000^b^ | | 0.020 ± 0.002**^b^ | | 1.753 ± 0.425** | 16.035 ± 2.311**^b^
µg Fullerene C_60_/total bronchial lymph node per mg fullerene C_60_/m^3^
Day 88 | NA | | 0.010 ± 0.001^b^ | | 0.117 ± 0.028 | 0.535 ± 0.077^b^
Spleen
Absolute spleen wt. (g)
Day 88 | 0.057 ± 0.002 | | 0.064 ± 0.002 | | 0.058 ± 0.001 | 0.061 ± 0.002
µg Fullerene C_60_/g spleen
Day 88 | 0.114 ± 0.000^c^ | | 0.114 ± 0.000c | | 1.673 ± 1.209 | 2.840 ± 2.220^c^
µg Fullerene C_60_/total spleen
Day 88 | 0.006 ± 0.000^c^ | | 0.008 ± 0.000^c^ | | 0.099 ± 0.072 | 0.185 ± 0.151^c^
µg Fullerene C_60_/total spleen per mg fullerene C_60_/m^3^
Day 88 | NA | | 0.004 ± 0.000^c^ | | 0.007 ± 0.005 | 0.006 ± 0.005^c^
Liver
Absolute liver wt. (g)
Day 88 | 1.265 ± 0.030 | | 1.320 ± 0.043^d^ | | 1.186 ± 0.034 | 1.196 ± 0.048
µg Fullerene C_60_/g liver
Day 88 | 0.006 ± 0.000^d^ | | 0.006 ± 0.000 | | 0.272 ± 0.161* | 0.529 ± 0.456*^d^
µg Fullerene C_60_/total liver
Day 88 | 0.007 ± 0.000^d^ | | 0.008 ± 0.000^d^ | | 0.309 ± 0.182** | 0.679 ± 0.601*^d^
µg Fullerene C_60_/total liver per mg fullerene C_60_/m^3^
Day 88 | NA | | 0.004 ± 0.000^d^ | | 0.021 ± 0.012 | 0.023 ± 0.020^d^
Lung
Absolute lung wt. (g)
Day 88 | 0.159 ± 0.015 | | 0.159 ± 0.005 | | 0.159 ± 0.008 | 0.177 ± 0.004*
PE Day 14 | 0.153 ± 0.006 | | 0.154 ± 0.002 | | 0.154 ± 0.002 | 0.168 ± 0.006
PE Day 28 | 0.155 ± 0.006 | | 0.160 ± 0.008 | | 0.169 ± 0.004 | 0.179 ± 0.016*
PE Day 56 | 0.158 ± 0.005 | | 0.170 ± 0.005 | | 0.175 ± 0.005* | 0.188 ± 0.003**
µg Fullerene C_60_/g lung
Day 88 | 0.090 ± 0.000^b^ | | 245.990 ± 20.016**^b^ | | 1,331.375 ± 79.440** | 3,335.689 ± 246.179**^b^
PE Day 14 | 0.090 ± 0.000 | | 118.681 ± 7.618** | | 674.684 ± 20.066** | 3,425.57 ± 340.797**
PE Day 28 | 0.090 ± 0.000 | | 72.130 ± 3.682** | | 425.722 ± 39.064** | 2,605.80 ± 361.820**
PE Day 56 | 0.090 ± 0.000^b^ | | 33.851 ± 3.454**^b^ | | 195.155 ± 38.049 | 1,846.59 ± 128.572**^b^
µg Fullerene C_60_/total lung
Day 88 | 0.015 ± 0.00^b^ | | 38.316 ± 2.033**^b^ | | 209.469 ± 8.387** | 595.138 ± 40.532**^b^
PE Day 14 | 0.014 ± 0.001 | | 18.202 ± 1.027** | | 103.728 ± 3.788** | 572.117 ± 53.954**
PE Day 28 | 0.014 ± 0.001 | | 11.423 ± 0.409** | | 72.064 ± 7.087** | 440.291 ± 25.214**
PE Day 56 | 0.014 ± 0.000^b^ | | 5.683 ± 0.471**^b^ | | 34.169 ± 6.639** | 347.127 ± 28.898**^b^
µg Fullerene C_60_/total lung per mg fullerene C_60_/m^3^
Day 88 | NA | | 19.16 ± 1.02^b^ | | 13.97 ± 0.56 | 19.84 ± 1.35^b^
PE Day 14 | NA | | 9.101 ± 0.513 | | 6.915 ± 0.253 | 19.071 ± 1.798
PE Day 28 | NA | | 5.712 ± 0.204 | | 4.804 ± 0.472 | 14.676 ± 0.840
PE Day 56 | NA | | 2.842 ± 0.236^b^ | | 2.278 ± 0.443 | 11.571 ± 0.963^b^
Female
n | 8 | | 8 | | 8 | 8
Bronchial Lymph Node
Absolute bronchial lymph node wt. (g)
Day 88 | 0.009 ± 0.001 | | 0.012 ± 0.003 | | 0.009 ± 0.001 | 0.011 ± 0.001
µg Fullerene C_60_/g bronchial lymph node
Day 88 | 1.111 ± 0.110^e^ | | 2.092 ± 0.356*^e^ | | 80.680 ± 17.315** | 1,696.586 ± 255.975**^e^
µg Fullerene C_60_/total bronchial lymph node
Day 88 | 0.009 ± 0.000^e^ | | 0.021 ± 0.002**^e^ | | 0.609 ± 0.063** | 17.415 ± 1.470**^e^
µg Fullerene C_60_/total bronchial lymph node per mg fullerene C_60_/m^3^
Day 88 | NA | | 0.010 ± 0.001^e^ | | 0.041 ± 0.004 | 0.580 ± 0.049^e^
Spleen
Absolute spleen wt. (g)
Day 88 | 0.086 ± 0.005 | | 0.076 ± 0.002 | | 0.082 ± 0.005 | 0.078 ± 0.001
µg Fullerene C_60_/g spleen
Day 88 | 0.114 ± 0.000^f^ | | 0.114 ± 0.000^f^ | | 0.288 ± 0.117 | 2.180 ± 1.945*^f^
µg Fullerene C_60_/total spleen
Day 88 | 0.010 ± 0.001^f^ | | 0.009 ± 0.000^f^ | | 0.022 ± 0.009 | 0.159 ± 0.140^f^
µg Fullerene C_60_/total spleen per mg fullerene C_60_/m^3^
Day 88 | NA | | 0.004 ± 0.000^f^ | | 0.001 ± 0.001 | 0.005 ± 0.005^f^
Liver
Absolute liver wt. (g)
Day 88 | 1.208 ± 0.051 | | 1.108 ± 0.028 | | 1.075 ± 0.037* | 1.086 ± 0.012
µg Fullerene C_60_/g liver
Day 88 | 0.006 ± 0.000^b^ | | 0.006 ± 0.000^b^ | | 0.097 ± 0.039** | 0.112 ± 0.018**^b^
µg Fullerene C_60_/total liver
Day 88 | 0.007 ± 0.000^b^ | | 0.007 ± 0.000^b^ | | 0.106 ± 0.043** | 0.123 ± 0.021**^b^
µg Fullerene C_60_/total liver per mg fullerene C_60_/m^3^
Day 88 | NA | | 0.003 ± 0.000^b^ | | 0.007 ± 0.003 | 0.004 ± 0.001^b^
Lung
Absolute lung wt. (g)
Day 88 | 0.147 ± 0.003 | | 0.151 ± 0.003 | | 0.147 ± 0.003 | 0.167 ± 0.003**
µg Fullerene C_60_/g lung
Day 88 | 0.090 ± 0.000^e^ | | 242.169 ± 8.996**^e^ | | 1,294.840 ± 41.845** | 3,386.537 ± 100.480**^e^
µg Fullerene C_60_/total lung
Day 88 | 0.013 ± 0.000^e^ | | 36.109 ± 1.111**^e^ | | 189.975 ± 5.211** | 560.250 ± 14.158**^e^
µg Fullerene C_60_/total liver per mg fullerene C_60_/m^3^
Day 88 | NA | | 18.055 ± 0.556^e^ | | 12.665 ± 0.347 | 18.675 ± 0.472^e^

* Significantly different (p ≤ 0.05) from the control group by Dunn’s or Shirley’s test; **p ≤ 0.01.

NA = not applicable; PE = postexposure.

^a^ Data are presented as mean ± standard error. Statistical tests were not performed on data that were normalized to fullerene C_60_ exposure concentration.

^b^ n = 5.

^c^ n = 4.

^d^ n = 3.

^e^ n = 7.

^f^ n = 6.

Table B-6 Lung Deposition and Clearance Parameter Estimates for Male Mice in the Three-month Nose-only Inhalation Study of Fullerene Micro-C_60_ (1 µm)^a^

Parameter | 2 mg/m^3^ | 15 mg/m^3^ | 30 mg/m^3^
A_0_ (µg fullerene C_60_/total lung) | 37 | 204 | 615
k (days^−1^) | 0.044 | 0.039 | 0.010
t_1/2_ (days) | 16 | 18 | 68
α (µg fullerene C_60_/total lung per day) | 2 | 8 | 11
A_e_ (µg fullerene C_60_/total lung) | 38 | 211 | 1,038

A_0_ = lung burden at t = 0 days postexposure; k = first-order lung clearance rate constant; t_1/2_ = lung clearance half-life; α = lung deposition rate; A_e_ = steady-state lung burden.

^a^ Data are presented as mean values.

Table B-7 Tissue Weights, Fullerene C_60_ Concentrations, and Fullerene C_60_ Burdens for Mice in the Three-month Nose-only Inhalation Study of Fullerene Nano-C_60_ (50 nm)^a^

| 0 mg/m^3^ | 0.5 mg/m^3^ | 2 mg/m^3^
Male
n | 6 | 6 | 6
Bronchial Lymph Node
Absolute bronchial lymph node wt. (g)
Day 89 | 0.009 ± 0.001 | 0.022 ± 0.008 | 0.016 ± 0.002
µg Fullerene C_60_/g bronchial lymph node
Day 89 | 0.596 ± 0.243^b^ | 2.040 ± 0.626*^b^ | 39.160 ± 26.831*^b^
µg Fullerene C_60_/bronchial lymph node
Day 89 | 0.005 ± 0.002^b^ | 0.025 ± 0.003**^b^ | 0.760 ± 0.548**^b^
µg Fullerene C_60_/total bronchial lymph node per mg fullerene C_60_/m^3^
Day 89 | NA | 0.050 ± 0.007^b^ | 0.380 ± 0.274^b^
Spleen
Absolute spleen wt. (g)
Day 89 | 0.049 ± 0.010 | 0.056 ± 0.002 | 0.060 ± 0.003
µg Fullerene C_60_/g spleen
Day 89 | 0.114 ± 0.000^c^ | 0.114 ± 0.000^c^ | 0.166 ± 0.052^c^
µg Fullerene C_60_/total spleen
Day 89 | 0.005 ± 0.002^c^ | 0.007 ± 0.000^c^ | 0.010 ± 0.003^c^
µg Fullerene C_60_/total spleen per mg fullerene C_60_/m^3^
Day 89 | NA | 0.013 ± 0.001^c^ | 0.005 ± 0.002^c^
Liver
Absolute liver wt. (g)
Day 89 | 1.133 ± 0.042 | 1.225 ± 0.043 | 1.171 ± 0.025
µg Fullerene C_60_/g liver
Day 89 | 0.006 ± 0.000^d^ | 0.006 ± 0.000^d^ | 0.037 ± 0.011*^d^
µg Fullerene C_60_/total liver
Day 89 | 0.007 ± 0.000^d^ | 0.008 ± 0.000^d^ | 0.042 ± 0.011^d^
µg Fullerene C_60_/total liver per mg fullerene C_60_/m^3^
Day 89 | NA | 0.015 ± 0.001^d^ | 0.021 ± 0.006^d^
Lung
Absolute lung wt. (g)
Day 89 | 0.153 ± 0.006 | 0.151 ± 0.009 | 0.159 ± 0.004
PE day 14 | 0.148 ± 0.004 | 0.171 ± 0.005** | 0.161 ± 0.003
PE day 28 | 0.148 ± 0.003 | 0.174 ± 0.005** | 0.167 ± 0.009
PE day 56 | 0.154 ± 0.003 | 0.175 ± 0.005** | 0.186 ± 0.007**
µg Fullerene C_60_/g lung
Day 89 | 0.090 ± 0.000^b^ | 157.971 ± 10.880**^b^ | 732.025 ± 28.837**^b^
PE day 14 | 0.090 ± 0.000 | 70.457 ± 4.027** | 396.547 ± 19.776**
PE day 28 | 0.090 ± 0.000 | 46.434 ± 3.036** | 172.877 ± 12.197**
PE day 56 | 0.090 ± 0.000^b^ | 20.290 ± 1.415**^b^ | 45.875 ± 2.941**^b^
µg Fullerene C_60_/total lung
Day 89 | 0.014 ± 0.001^b^ | 23.714 ± 2.158**^b^ | 115.390 ± 2.747**^b^
PE day 14 | 0.013 ± 0.000 | 12.112 ± 0.815** | 63.659 ± 0.815**
PE day 28 | 0.013 ± 0.000 | 8.104 ± 0.575** | 28.571 ± 1.784**
PE day 56 | 0.014 ± 0.000^b^ | 3.513 ± 0.248**^b^ | 8.548 ± 0.689**^b^
µg Fullerene C_60_/total lung per mg fullerene C_60_/m^3^
Day 89 | NA | 47.43 ± 4.32^b^ | 57.70 ± 1.37^b^
PE day 14 | NA | 24.224 ± 1.631 | 31.829 ± 1.711
PE day 28 | NA | 16.207 ± 1.149 | 14.285 ± 0.892
PE day 56 | NA | 7.026 ± 0.495^b^ | 4.274 ± 0.345^b^
Female
n | 8 | 8 | 8
Bronchial Lymph Node
Absolute bronchial lymph node wt. (g)
Day 89 | 0.009 ± 0.003 | 0.013 ± 0.004 | 0.010 ± 0.002
µg Fullerene C_60_/g bronchial lymph node
Day 89 | 1.144 ± 0.233^e^ | 3.463 ± 0.757**^e^ | 17.177 ± 4.699**^e^
µg Fullerene C_60_/total bronchial lymph node
Day 89 | 0.008 ± 0.001^e^ | 0.036 ± 0.007**^e^ | 0.140 ± 0.031**^e^
µg Fullerene C_60_/total bronchial lymph node per mg fullerene C_60_/m^3^
Day 89 | NA | 0.071 ± 0.013^e^ | 0.070 ± 0.015^e^
Spleen
Absolute spleen wt. (g)
Day 89 | 0.076 ± 0.002 | 0.078 ± 0.002 | 0.075 ± 0.002
µg Fullerene C_60_/g spleen
Day 89 | 0.114 ± 0.000^f^ | 0.114 ± 0.000^f^ | 0.114 ± 0.003^f^
µg Fullerene C_60_/total spleen
Day 89 | 0.009 ± 0.000^f^ | 0.009 ± 0.000^f^ | 0.009 ± 0.000^f^
µg Fullerene C_60_/total spleen per mg fullerene C_60_/m^3^
Day 89 | NA | 0.018 ± 0.001^f^ | 0.004 ± 0.000^f^
Liver
Absolute liver wt. (g)
Day 89 | 1.095 ± 0.015 | 1.063 ± 0.016 | 1.007 ± 0.017**
µg Fullerene C_60_/g liver
Day 89 | 0.006 ± 0.000^b^ | 0.006 ± 0.000^b^ | 0.070 ± 0.003**^b^
µg Fullerene C_60_/total liver
Day 89 | 0.006 ± 0.000^b^ | 0.006 ± 0.000^b^ | 0.071 ± 0.004**^b^
µg Fullerene C_60_/total liver per mg fullerene C_60_/m^3^
Day 89 | NA | 0.013 ± 0.000^b^ | 0.035 ± 0.002^b^
Lung
Absolute lung wt. (g)
Day 89 | 0.140 ± 0.008 | 0.151 ± 0.004 | 0.144 ± 0.006
µg Fullerene C_60_/g lung
Day 89 | 0.090 ± 0.000^e^ | 169.635 ± 4.139**^e^ | 685.230 ± 31.611**^e^
µg Fullerene C_60_/total lung
Day 89 | 0.012 ± 0.001^e^ | 25.658 ± 1.006**^e^ | 97.530 ± 5.935**^e^
µg Fullerene C_60_/total lung per mg fullerene C_60_/m^3^
Day 89 | NA | 57.317 ± 2.011^e^ | 48.765 ± 2.967^e^

* Significantly different (p ≤ 0.05) from the control group by Dunn’s or Shirley’s test; **p ≤ 0.01.

^a^ Data are presented as mean ± standard error. Statistical tests were not performed on data that were normalized to fullerene C_60_ exposure concentration. NA = not applicable; PE = postexposure.

^b^ n = 5.

^c^ n = 4.

^d^ n = 3.

^e^ n = 7.

^f^ n = 6.

Table B-8 Lung Deposition and Clearance Parameter Estimates for Male Mice in the Three-month Nose-only Inhalation Study of Fullerene Nano-C_60_ (50 nm)^a^

Parameter | 0.5 mg/m^3^ | 2 mg/m^3^
A_0_ (µg fullerene C_60_/total lung) | 23 | 116
k (days^−1^) | 0.040 | 0.047
t_1/2_ (days) | 17 | 15
α (µg fullerene C_60_/total lung per day) | 0.9 | 5.5
A_e_ (µg fullerene C_60_/total lung) | 24 | 118

A_0_ = lung burden at t = 0 days postexposure; k = first-order lung clearance rate constant; t_1/2_ = lung clearance half-life; α = lung deposition rate; A_e_ = steady-state lung burden.

^a^ Data are presented as mean values.