# Appendix A Reproductive Tissue Evaluations and Estrous Cycle Characterization

Table A-1 Summary of Reproductive Tissue Evaluations for Male Rats in the Three-month Nose-only Inhalation Study of Fullerene Micro-C_60_ (1 µm)^a^

| 0 mg/m^3^ | 2 mg/m^3^ | 15 mg/m^3^ | 30 mg/m^3^
n | 10 | 10 | 10 | 10
Weights (g)
Necropsy body wt. | 353 ± 12 | 350 ± 10 | 373 ± 16 | 368 ± 9
L. Cauda epididymis | 0.2400 ± 0.0092 | 0.2430 ± 0.0088 | 0.2476 ± 0.0203 | 0.2443 ± 0.0068
L. Epididymis | 0.6829 ± 0.0220 | 0.6594 ± 0.0227 | 0.6727 ± 0.0443 | 0.6749 ± 0.0187
L. Testis | 1.8296 ± 0.0434 | 1.8348 ± 0.0563 | 1.8040 ± 0.1605 | 1.8206 ± 0.0318
Spermatid Measurements
Spermatid heads (10^3^/mg testis) | 137.9 ± 7.1 | 138.1 ± 4.4 | 118.0 ± 15.0 | 122.3 ± 3.2
Spermatid heads (10^6^/testis) | 250.8 ± 11.3 | 252.9 ± 9.6 | 228.3 ± 27.5 | 222.1 ± 4.8
Epididymal Spermatozoal Measurements
Sperm motility (%) | 84 ± 1 | 80 ± 1** | 74 ± 8* | 79 ± 1**
Sperm (10^3^/mg cauda epididymis) | 529 ± 19 | 587 ± 36 | 468 ± 66 | 532 ± 18
Sperm (10^6^/cauda epididymis) | 128 ± 7 | 143 ± 11 | 122 ± 17 | 130 ± 4

* Significantly different (p ≤ 0.05) from the control group by Shirley’s test; **p ≤ 0.01.

^a^ Data are presented as mean ± standard error. Differences from the control group are not significant by Dunnett’s test (body weights and tissue weights) or Dunn’s test (spermatid measurements and sperm/mg cauda epididymis and per cauda epididymis).

Table A-2 Summary of Reproductive Tissue Evaluations for Male Rats in the Three-month Nose-only Inhalation Study of Fullerene Nano-C_60_ (50 nm)^a^

| 0 mg/m^3^ | 0.5 mg/m^3^ | 2 mg/m^3^
n | 10 | 10 | 10
Weights (g)
Necropsy body wt. | 362 ± 10 | 360 ± 12 | 356 ± 9
L. Cauda epididymis | 0.2403 ± 0.0099 | 0.2325 ± 0.0123 | 0.2384 ± 0.0141
L. Epididymis | 0.6741 ± 0.0235 | 0.6392 ± 0.0218 | 0.6498 ± 0.0274
L. Testis | 1.8168 ± 0.0465 | 1.7605 ± 0.0819 | 1.8299 ± 0.0551
Spermatid Measurements
Spermatid heads (10^3^/mg testis) | 141.8 ± 9.0 | 128.8 ± 5.6 | 134.2 ± 12.1
Spermatid heads (10^6^/testis) | 256.40 ± 15.65 | 225.73 ± 11.63 | 248.76 ± 24.41
Epididymal Spermatozoal Measurements
Sperm motility (%) | 85 ± 1 | 82 ± 1 | 71 ± 8**
Sperm (10^3^/mg cauda epididymis) | 625 ± 39 | 626 ± 54 | 479 ± 68
Sperm (10^6^/cauda epididymis) | 150 ± 10 | 145 ± 15 | 122 ± 19

** Significantly different (p ≤ 0.01) from the control group by Shirley’s test.

^a^ Data are presented as mean ± standard error. Differences from the control group are not significant by Dunnett’s test (body weights and tissue weights) or Dunn’s test (spermatid measurements and sperm/mg cauda epididymis and per cauda epididymis).

Table A-3 . Summary of Reproductive Tissue Evaluations for Male Mice in the Three-month Nose-only Inhalation Study of Fullerene Micro-C_60_ (1 µm)^a^

| 0 mg/m^3^ | 2 mg/m^3^ | 15 mg/m^3^ | 30 mg/m^3^
n | 10 | 9 | 10 | 10
Weights (g)
Necropsy body wt. | 31.6 ± 0.7 | 32.1 ± 0.9 | 30.9 ± 0.5 | 31.3 ± 0.7
L. Cauda epididymis | 0.0156 ± 0.0005 | 0.0176 ± 0.0021 | 0.0193 ± 0.0015 | 0.0172 ± 0.0013
L. Epididymis | 0.0483 ± 0.0019 | 0.0458 ± 0.0009 | 0.0489 ± 0.0021 | 0.0476 ± 0.0026
L. Testis | 0.1088 ± 0.0021 | 0.0978 ± 0.0109 | 0.1056 ± 0.0025 | 0.1092 ± 0.0013
Spermatid Measurements
Spermatid heads (10^3^/mg testis) | 323.3 ± 21.2 | 274.8 ± 35.0 | 283.0 ± 10.9 | 321.4 ± 21.6
Spermatid heads (10^6^/testis) | 35.14 ± 2.29 | 29.82 ± 3.98 | 29.88 ± 1.35 | 34.89 ± 1.98
Epididymal Spermatozoal Measurements
Sperm motility (%) | 83 ± 1 | 72 ± 9* | 78 ± 1** | 76 ± 3*
Sperm (10^3^/mg cauda epididymis) | 527 ± 38 | 429 ± 70 | 477 ± 32 | 552 ± 71
Sperm (10^6^/cauda epididymis) | 8 ± 0 | 7 ± 1 | 9 ± 1 | 9 ± 1

* Significantly different (p ≤ 0.05) from the control group by Shirley’s test; **p ≤ 0.01.

^a^ Data are presented as mean ± standard error. Differences from the control group are not significant by Dunnett’s test (body weights and left epididymis weights) or Dunn’s test (spermatid measurements and sperm/mg cauda epididymis and per cauda epididymis).

Table A-4 Estrous Cycle Characterization for Female Mice in the Three-month Nose-only Inhalation Study of Fullerene Micro-C_60_ (1 µm)^a^

| 0 mg/m^3^ | 2 mg/m^3^ | 15 mg/m^3^ | 30 mg/m^3^
Number Weighed at Necropsy | 10 | 10 | 10 | 10
Necropsy body wt. (g) | 28.1 ± 0.6 | 28.4 ± 0.7 | 27.9 ± 0.5 | 28.6 ± 0.8
Proportion of Regular Cycling Females^b^ | 10/10 | 10/10 | 9/10 | 10/10
Estrous Cycle Length (days) | 4.5 ± 0.18 | 4.1 ± 0.21 | 4.6 ± 0.16 | 4.4 ± 0.14
Estrous Stages (% of cycle)
Diestrus | 34.4 | 32.5 | 26.9 | 28.1
Proestrus | 0.6 | 1.3 | 1.9 | 0.6
Estrus | 51.3 | 52.5 | 50.6 | 51.9
Metestrus | 8.1 | 8.1 | 6.9 | 9.4
Uncertain diagnosis | 5.6 | 5.6 | 13.8 | 10.0

^a^ Necropsy body weights and estrous cycle length data are presented as mean ± standard error. Differences from the control group are not significant by Dunnett’s test (body weights) or Dunn’s test (estrous cycle length). Tests for equality of transition probability matrices among all groups and between the control group and each exposed group indicated females exposed to 15 mg/m^3^ had increased probability of extended estrus compared to the control group.

^b^ Number of females with a regular cycle/number of females cycling.

Table A-5 Results of Vaginal Cytology Study Using the Transition Matrix Approach for Female Mice in the Three-month Nose-only Inhalation Study of Fullerene Micro-C_60_ (1 µm)

Stage | Comparison | P Value | Trend^a^
Overall Tests | Overall | 0.065
Overall Tests | 2 mg/m^3^ vs. controls | 0.829 | –
Overall Tests | 15 mg/m^3^ vs. controls | 0.008 | –
Overall Tests | 30 mg/m^3^ vs. controls | 0.408 | –
Extended Estrus | Overall | 0.24
Extended Estrus | 2 mg/m^3^ vs. controls | 0.93 | N
Extended Estrus | 15 mg/m^3^ vs. controls | 0.034 | –
Extended Estrus | 30 mg/m^3^ vs. controls | 0.586 | –
Extended Diestrus | Overall | 0.587
Extended Diestrus | 2 mg/m^3^ vs. controls | 0.217 | –
Extended Diestrus | 15 mg/m^3^ vs. controls | 0.447 | –
Extended Diestrus | 30 mg/m^3^ vs. controls | 0.996 | –
Extended Metestrus | Overall | 0.92
Extended Metestrus | 2 mg/m^3^ vs. controls | 1 | –
Extended Metestrus | 15 mg/m^3^ vs. controls | 0.607 | –
Extended Metestrus | 30 mg/m^3^ vs. controls | 0.607 | –
Extended Proestrus | Overall | 1
Extended Proestrus | 2 mg/m^3^ vs. controls | 1 | –
Extended Proestrus | 15 mg/m^3^ vs. controls | 1 | –
Extended Proestrus | 30 mg/m^3^ vs. controls | 1 | –
Skipped Estrus | Overall | 1
Skipped Estrus | 2 mg/m^3^ vs. controls | 0.931 | –
Skipped Estrus | 15 mg/m^3^ vs. controls | 1 | –
Skipped Estrus | 30 mg/m^3^ vs. controls | 1 | –
Skipped Diestrus | Overall | 0.1
Skipped Diestrus | 2 mg/m^3^ vs. controls | 0.043 | –
Skipped Diestrus | 15 mg/m^3^ vs. controls | 0.359 | N
Skipped Diestrus | 30 mg/m^3^ vs. controls | 0.251 | –
Summary of Significant Groups
Overall Tests | 15 mg/m^3^ vs. controls | 0.008 | –
Extended Estrus | 15 mg/m^3^ vs. controls | 0.034 | –
Skipped Diestrus | 2 mg/m^3^ vs. controls | 0.043 | –

^a^ N means that the exposed group had a lower probability of transitioning to the relevant abnormal state (extended estrus, extended metestrus, extended proestrus, skipped estrus, or skipped diestrus) than did the control group.

Table A-6 Summary of Reproductive Tissue Evaluations for Male Mice in the Three-month Nose-only Inhalation Study of Fullerene Nano-C_60_ (50 nm)^a^

| 0 mg/m^3^ | 0.5 mg/m^3^ | 2 mg/m^3^
n | 10 | 10 | 10
Weights (g)
Necropsy body wt. | 31.5 ± 0.8 | 31.7 ± 1.1 | 31.3 ± 0.6
L. Cauda epididymis | 0.0181 ± 0.0010 | 0.0164 ± 0.0012 | 0.0163 ± 0.0006
L. Epididymis | 0.0479 ± 0.0017 | 0.0445 ± 0.0020 | 0.0459 ± 0.0019
L. Testis | 0.1057 ± 0.0015 | 0.1065 ± 0.0020 | 0.1076 ± 0.0018
Spermatid Measurements
Spermatid heads (10^3^/mg testis) | 355.6 ± 21.7 | 322.2 ± 23.4 | 319.3 ± 28.5
Spermatid heads (10^6^/testis) | 37.42 ± 1.91 | 34.24 ± 2.46 | 34.43 ± 3.12
Epididymal Spermatozoal Measurements
Sperm motility (%) | 78 ± 2 | 71 ± 5 | 75 ± 2
Sperm (10^3^/mg cauda epididymis) | 477 ± 55 | 623 ± 61 | 846 ± 141
Sperm (10^6^/cauda epididymis) | 9 ± 1 | 10 ± 1 | 14 ± 2

^a^ Data are presented as mean ± standard error. Differences from the control group are not significant by Dunnett’s test (body weights and tissue weights) or Dunn’s test (spermatid and epididymal spermatozoal measurements).

Table A-7 Estrous Cycle Characterization for Female Mice in the Three-month Nose-only Inhalation Study of Fullerene Nano-C_60_ (50 nm)^a^

| 0 mg/m^3^ | 0.5 mg/m^3^ | 2 mg/m^3^
Number Weighed at Necropsy | 10 | 10 | 10
Necropsy Body Wt. (g) | 26.5 ± 0.5 | 27.9 ± 0.7 | 26.6 ± 0.4
Proportion of Regular Cycling Females^b^ | 10/10 | 10/10 | 10/10
Estrous Cycle Length (days) | 4.2 ± 0.13 | 4.5 ± 0.20 | 4.5 ± 0.13
Estrous stages (% of cycle)
Diestrus | 26.3 | 31.3 | 33.8
Proestrus | 3.8 | 2.5 | 3.1
Estrus | 45.6 | 51.9 | 52.5
Metestrus | 16.9 | 8.8 | 8.8
Uncertain diagnosis | 7.5 | 5.6 | 1.9

^a^ Necropsy body weights and estrous cycle length data are presented as mean ± standard error. Differences from the control group are not significant by Dunnett’s test (body weights) or Dunn’s test (estrous cycle length). Tests for equality of transition probability matrices among all groups and between the control group and each exposed group indicated exposed females had an increased probability of extended estrus compared to the control group.

^b^ Number of females with a regular cycle/number of females cycling.

Table A-8 Results of Vaginal Cytology Study Using the Transition Matrix Approach for Female Mice in the Three-month Nose-only Inhalation Study of Fullerene Nano-C_60_ (50 nm)

Stage | Comparison | P Value | Trend^a^
Overall Tests | Overall | 0.122
Overall Tests | 0.5 mg/m^3^ vs. controls | 0.52 | –
Overall Tests | 2 mg/m^3^ vs. controls | 0.051 | –
Extended Estrus | Overall | <0.001
Extended Estrus | 0.5 mg/m^3^ vs. controls | 0.002 | –
Extended Estrus | 2 mg/m^3^ vs. controls | <0.001 | –
Extended Diestrus | Overall | 0.909
Extended Diestrus | 0.5 mg/m^3^ vs. controls | 0.604 | –
Extended Diestrus | 2 mg/m^3^ vs. controls | 1 | –
Extended Metestrus | Overall | 1
Extended Metestrus | 0.5 mg/m^3^ vs. controls | 1 | –
Extended Metestrus | 2 mg/m^3^ vs. controls | 1 | –
Extended Proestrus | Overall | 1
Extended Proestrus | 0.5 mg/m^3^ vs. controls | 1 | –
Extended Proestrus | 2 mg/m^3^ vs. controls | 1 | –
Skipped Estrus | Overall | 1
Skipped Estrus | 0.5 mg/m^3^ vs. controls | 1 | –
Skipped Estrus | 2 mg/m^3^ vs. controls | 1 | –
Skipped Diestrus | Overall | 0.993
Skipped Diestrus | 0.5 mg/m^3^ vs. controls | 0.931 | –
Skipped Diestrus | 2 mg/m^3^ vs. controls | 0.934 | –
Summary of Significant Groups
Extended Estrus | 0.5 mg/m^3^ vs. controls | 0.002 | –
Extended Estrus | 2 mg/m^3^ vs. controls | <0.001 | –

^a^ N means that the exposed group had a lower probability of transitioning to the relevant abnormal state (extended estrus, extended metestrus, extended proestrus, skipped estrus, or skipped diestrus) than did the control group.

Figure A-1

Vaginal Cytology Plots for Female Mice in the Three-month Nose-only Inhalation Study of Fullerene Micro-C_60_ (1 µm)

P = proestrus; E = estrus; M = metestrus; D = diestrus; IC = insufficient number of cells to determine stage.

Figure A-2

Vaginal Cytology Plots for Female Mice in the Three-month Nose-only Inhalation Study of Fullerene Nano-C_60_ (50 nm)

P = proestrus; E = estrus; M = metestrus; D = diestrus; IC = insufficient number of cells to determine stage.