# Publication Details

Publisher: National Toxicology Program

Publishing Location: Research Triangle Park, NC

ISSN: 2378-8992

DOI: https://doi.org/10.22427/NTP-TOX-86

Report Series: NTP Toxicity Report Series

Report Series Number: 86

Official citation: National Toxicology Program (NTP). 2016. NTP technical report on the toxicity studies of cedarwood oil (Virginia) (CASRN 8000-27-9) administered dermally to F344/N rats and B6C3F1/N mice. Research Triangle Park, NC: National Toxicology Program. Toxicity Report 86.