# Peer Review

The draft NTP Technical Report on the Toxicity Studies of Cedarwood Oil (Virginia) (CASRN 8000-27-9) Administered Dermally to F344/N Rats and B6C3F1/N Mice was evaluated by the reviewers listed below. These reviewers served as independent scientists, not as representatives of any institution, company, or governmental agency. In this capacity, reviewers determined if the design and conditions of these NTP studies were appropriate and ensured that this Toxicity Study Report presented the experimental results and conclusions fully and clearly.

## Peer Reviewers

- Gregory L. Erexson, Ph.D.
  Preclinical Safety
  Research & Development
  AbbVie, Inc.
  North Chicago, Illinois, USA
- Laura A. Hansen, Ph.D.
  Department of Biomedical Sciences
  Creighton University School of Medicine
  Omaha, Nebraska, USA