# Collaborators

- Division of the National Toxicology Program, National Institute of Environmental Health Sciences, Research Triangle Park, North Carolina, USA
  Evaluated and interpreted results and reported findings
  N.R. Catlin, Ph.D., Study Scientist
  R.A. Herbert, D.V.M., Ph.D., Study Pathologist
  C.R. Blystone, Ph.D.
  P.M. Foster, Ph.D.
  M.J. Hooth, Ph.D.
  A.P. King-Herbert, D.V.M.
  G.E. Kissling, Ph.D.
  D.E. Malarkey, D.V.M., Ph.D.
  B.S. McIntyre, Ph.D.
  S.L. Smith-Roe, Ph.D.
  M.D. Stout, Ph.D.
  I.O. Surh, Ph.D.
  G.S. Travlos, D.V.M.
  M.K. Vallant, M.T.
  S. Waidyanatha, Ph.D.
  N.J. Walker, Ph.D.
  K.L. Witt, M.S.
- Battelle Columbus Operations, Columbus, Ohio, USA
  Conducted studies and evaluated pathology findings
  M.R. Hejtmancik, Ph.D., Principal Investigator
  C.A. Colleton, D.V.M.
  L.M. Fomby, D.V.M., Ph.D.
  M.J. Ryan, D.V.M., Ph.D.
  J.D. Toft, II, D.V.M.
- Experimental Pathology Laboratories, Inc., Research Triangle Park, North Carolina, USA
  Conducted pathology review
  M.H. Hamlin, II, D.V.M., Principal Investigator
  M.M. Gruebbel, D.V.M., Ph.D.
  R.A. Miller, D.V.M., Ph.D.
  R.R. Moore, D.V.M., Ph.D.
- Coordinated NTP Pathology Peer Review (Special Report; November 7, 2013)
  R.R. Moore, D.V.M., Ph.D.
- ILS, Inc., Research Triangle Park, North Carolina, USA
  Coordinated NTP Pathology Working Group (April 5, 2007)
  G.D. Hill, D.V.M., Ph.D.
- Bridge Global Pharmaceutical Services, Inc., Gaithersburg, Maryland, USA
  Provided SMVCE analysis
  B.J.T. Muir, Ph.D., Principal Investigator
  B. Atkinson, M.Sc.
  Y. Wang, M.S.