# References

1 The Merck Index. 11th ed. Rahway (NJ): Merck and Company; 1989.
2 Ciesla W. Non-wood forest products from conifers In: Non-Wood Forest Products, Vol. 12. Rome, Italy: Food and Agriculture Organization of the United Nations (FAO); 1998.
3 Coppen J. Flavours and fragrances of plant origin In: Non-Wood Forest Products, Vol. 1. Rome, Italy: Food and Agriculture Organization of the United Nations (FAO); 1995.
4 Dunford NT Hiziroglu S Holcomb R Effect of age on the distribution of oil in Eastern redcedar tree segments. Bioresour Technol. 2007;98(14):2636–2640. http://dx.doi.org/10.1016/j.biortech.2006.09.058 17141500
5 Franz H Frank R Rytter M Haustein UF Allergic contact dermatitis due to cedarwood oil after dermatoscopy. Contact Dermat. 1998;38(3):182–183. http://dx.doi.org/10.1111/j.1600-0536.1998.tb05701.x 9536426
6 Gerhartz W Ullmann’s encyclopedia of industrial chemistry. Deerfield Beach (FL): VCH Publishers; 1985. p. 220.
7 Merory J Food flavorings: Composition, manufacture, and use. 2nd ed. Westport (CT): AVI Publishing Company, Inc; 1968.
8 United States Environmental Protection Agency (USEPA). Reregistration Eligibility Decision (RED): Cedarwood oil. Washington, DC: US Environmental Protection Agency, Office of Prevention, Pesticides and Toxic Substances; 1993. EPA-723-S-93-012. https://web.archive.org/web/20080619000737/https://www.epa.gov/oppsrrd1/REDs/old_reds/cedarwood_oil.pdf
9 International Organization for Standardization (ISO). Essential Oils. Oil of cedarwood, Virginian (Juniperus virginiana L) ISO 4724:2004€. 2004.
10 Hazardous Substance Data Bank (HSDB). Cedarwood oil. TOXNET: Toxicology Data Network, National Library of Medicine; 2014. https://toxnet.nlm.nih.gov/hsdb.htm [Accessed: July 2014]
11 Research Institute for Fragrance Materials (RIFM) Fragrance raw materials monographs: cedarwood oil Virginia. Food Cosmet Toxicol. 1974;12:845–846. http://dx.doi.org/10.1016/0015-6264(74)90147-3
12 Food and Drug Administration (FDA). Modification in voluntary filing of cosmetic product ingredient and cosmetic raw material composition statements. Federal Register Vol 57, No 18. Washington, DC; 1992. p. 3128-3130.
13 Cosmetic Ingredient Review (CIR) Final report on the safety assessment of Juniperus communis Extract, Juniperus oxycedrus Extract, Juniperus oxycedrus Tar, Juniperus phoenicea extract, and Juniperus virginiana Extract. Int J Toxicol. 2001;20 Suppl 2:41–56. http://dx.doi.org/10.1080/10915810160233758 11558640
14 Craig AM Karchesy JJ Blythe LL del Pilar González-Hernández M Swan LR Toxicity studies on western juniper oil (Juniperus occidentalis) and Port-Orford-cedar oil (Chamaecyparis lawsoniana) extracts utilizing local lymph node and acute dermal irritation assays. Toxicol Lett. 2004;154(3):217–224. http://dx.doi.org/10.1016/j.toxlet.2004.08.004 15501613
15 United States Environmental Protection Agency (USEPA). Wood oils and gums summary document. Washington, DC: US Environmental Protection Agency, Office of Prevention, Pesticides and Toxic Substances; 2009. Docket No. EPA-HQ-OPP-2009-0258. https://archive.epa.gov/oppsrrd1/registration_review/web/html/index-291.html
16 Barnard DR Repellency of essential oils to mosquitoes (Diptera: culicidae). J Med Entomol. 1999;36(5):625–629. http://dx.doi.org/10.1093/jmedent/36.5.625 10534958
17 Curtis CF Lines JD Ijumba J Callaghan A Hill N Karimzad MA The relative efficacy of repellents against mosquito vectors of disease. Med Vet Entomol. 1987;1(2):109–119. http://dx.doi.org/10.1111/j.1365-2915.1987.tb00331.x 2908762
18 Singh D Rao SM Tripathi AK Cedarwood oil as a potential insecticidal agent against mosquitoes. Naturwissenschaften. 1984;71(5):265–266. http://dx.doi.org/10.1007/BF00441340 6146933
19 Eller FJ Vander Meer RK Behle RW Flor-Weiler LB Palmquist DE Bioactivity of cedarwood oil and cedrol against arthropod pests. Environ Entomol. 2014;43(3):762–766. http://dx.doi.org/10.1603/EN13270 24690252
20 Takao Y Kuriyama I Yamada T Mizoguchi H Yoshida H Mizushina Y Antifungal properties of Japanese cedar essential oil from waste wood chips made from used sake barrels. Mol Med Rep. 2012;5(5):1163–1168. 22395293
21 Acevedo Z Abortion in early America. Women Health. 1979;4(2):159–167. http://dx.doi.org/10.1300/J013v04n02_05 10297561
22 Gosselin R Smith R Hodge H Clinical toxicology of commercial products. 5th ed. Baltimore (MD): Williams and Wilkins; 1984.
23 Welch KD Cook D Gardner DR Parsons C Pfister JA Panter KE A comparison of the abortifacient risk of western juniper trees in Oregon. Rangelands. 2013;35(1):40–44. http://dx.doi.org/10.2111/RANGELANDS-D-12-00056.1
24 National Institute for Occupational Safety and Health (NIOSH). National Occupational Exposure Survey (1981-1983) [unpublished provisional data]. Cincinnati, OH. 1990.
25 Code of Federal Regulations (CFR). 21:§172.515.
26 Code of Federal Regulations (CFR). 40:§152.125.
27 United States Environmental Protection Agency (USEPA). Cedarwood oil; Substance Registry Services (SRS) entry. 2013. https://ofmpub.epa.gov/sor_internet/registry/substreg/searchandretrieve/substancesearch/search.do?details=displayDetails&selectedSubstanceId=16188
28 Hong JY Lee BH Kim TH Hong J Lee KM Yoo SD Lee HS GC-MS/MS method for the quantification of α-cedrene in rat plasma and its pharmacokinetic application. J Sep Sci. 2013;36(21-22):3558–3562. http://dx.doi.org/10.1002/jssc.201300828 23996797
29 Kim TH Yoo SD Lee HS Lee KM Seok SH Kim MG Jung BH Kim MG Shin BS In vivo absorption and disposition of α-cedrene, a sesquiterpene constituent of cedarwood oil, in female and male rats. Drug Metab Pharmacokinet. 2015;30(2):168–173. http://dx.doi.org/10.1016/j.dmpk.2014.12.003 25857232
30 Frosch PJ Pilz B Andersen KE Burrows D Camarasa JG Dooms-Goossens A Ducombs G Fuchs T Hannuksela M Lachapelle JM Patch testing with fragrances: results of a multicenter study of the European Environmental and Contact Dermatitis Research Group with 48 frequently used constituents of perfumes. Contact Dermat. 1995;33(5):333–342. http://dx.doi.org/10.1111/j.1600-0536.1995.tb02048.x 8565489
31 Abifadel R Mortureux P Perromat M Ducombs G Taieb A Contact sensitivity to flavourings and perfumes in atopic dermatitis. Contact Dermat. 1992;27(1):43–46. http://dx.doi.org/10.1111/j.1600-0536.1992.tb05196.x 1424590
32 Fujii T Furukawa S Suzuki S Studies on compounded perfumes for toilet goods: on the non-irritative compounded perfumes for soaps [in Japanese, English abstract]. Journal of Japan Oil Chemists’ Society. 1972;21:904–908. https://doi.org/10.5650/jos1956.21.904
33 Kligman AM The identification of contact allergens by human assay. 3. The maximization test: a procedure for screening and rating contact sensitizers. J Invest Dermatol. 1966;47(5):393–409. http://dx.doi.org/10.1038/jid.1966.160 5924294
34 Belsito D Bickers D Bruze M Calow P Dagli ML Fryer AD Greim H Miyachi Y Saurat JH Sipes IG RIFM Expert Panel A toxicological and dermatological assessment of alkyl cyclic ketones when used as fragrance ingredients. Food Chem Toxicol. 2013;62 Suppl 1:S1–S44. http://dx.doi.org/10.1016/j.fct.2013.09.033 24246175
35 Lapczynski A Isola DA Christian MS Diener RM Api AM Evaluation of the developmental toxicity of acetyl cedrene. Int J Toxicol. 2006;25(5):423–428. http://dx.doi.org/10.1080/10915810600870575 16940015
36 Ogata A Ando H Kubo Y Nagasawa A Ogawa H Yasuda K Aoki N Teratogenicity of thujaplicin in ICR mice. Food Chem Toxicol. 1999;37(11):1097–1104. http://dx.doi.org/10.1016/S0278-6915(99)00097-6 10566881
37 Adams R Cedar wood oil analyses and properties. In: Linsken H Jackson Jeditors. Modern Methods of Plant Analysis New Series: Essential Oils and Waxes. Vol. 12. New York (NY): Springer-Verlag; 1991. p. 159–173. http://dx.doi.org/10.1007/978-3-642-84023-4_8
38 Adams R Identification of essential oils by ion trap mass spectrometry. San Diego (CA): Academic Press, Inc.; 1989.
39 Adams R Identification of essential oil components by gas chromatography/quadrupole mass spectroscopy. Carol Stream (IL): Allured Publishing Corporation; 2001.
40 Maronpot RR Boorman GA Interpretation of rodent hepatocellular proliferative alterations and hepatocellular tumors in chemical safety assessment. Toxicol Pathol. 1982;10(2):71–78. http://dx.doi.org/10.1177/019262338201000210 28094716
41 Boorman GA Montgomery CA Jr Eustis SL Wolfe MJ McConnell EE Hardisty JF Quality assurance in pathology for rodent carcinogenicity studies. In: Milman HA Weisburger EKeditors. Handbook of Carcinogen Testing. Park Ridge (NJ): Noyes Publications; 1985. p. 345–357.
42 Gart JJ Chu KC Tarone RE Statistical issues in interpretation of chronic bioassay tests for carcinogenicity. J Natl Cancer Inst. 1979;62(4):957–974. 285297
43 Dunnett CW A multiple comparison procedure for comparing several treatments with a control. J Am Stat Assoc. 1955;50(272):1096–1121. http://dx.doi.org/10.1080/01621459.1955.10501294
44 Williams DA A test for differences between treatment means when several dose levels are compared with a zero dose control. Biometrics. 1971;27(1):103–117. http://dx.doi.org/10.2307/2528930 5547548
45 Williams DA The comparison of several dose levels with a zero dose control. Biometrics. 1972;28(2):519–531. http://dx.doi.org/10.2307/2556164 5037867
46 Shirley E A non-parametric equivalent of Williams’ test for contrasting increasing dose levels of a treatment. Biometrics. 1977;33(2):386–389. http://dx.doi.org/10.2307/2529789 884197
47 Williams DA A note on Shirley’s nonparametric test for comparing several dose levels with a zero-dose control. Biometrics. 1986;42(1):183–186. http://dx.doi.org/10.2307/2531254 3719054
48 Dunn OJ Multiple comparisons using rank sums. Technometrics. 1964;6(3):241–252. http://dx.doi.org/10.1080/00401706.1964.10490181
49 Jonckheere A A distribution-free k-sample test against ordered alternatives. Biometrika. 1954;41:133–145. http://dx.doi.org/10.1093/biomet/41.1-2.133
50 Dixon W Massey F Introduction to statistical analysis. 2nd ed. New York (NY): McGraw Hill Book Company Inc; 1957. http://dx.doi.org/10.2307/2332898
51 Girard DM Sager DB The use of Markov chains to detect subtle variation in reproductive cycling. Biometrics. 1987;43(1):225–234. http://dx.doi.org/10.2307/2531963 3567307
52 Wilcoxon F. Individual comparisons by ranking methods. Biometrics Bull. 1945; 1(6):80-83. http://dx.doi.org/10.2307/3001968
53 Code of Federal Regulations (CFR). 21:Part 58.
54 Zeiger E Anderson B Haworth S Lawlor T Mortelmans K Salmonella mutagenicity tests: V. Results from the testing of 311 chemicals. Environ Mol Mutagen. 1992;19 Suppl 21:2–141. http://dx.doi.org/10.1002/em.2850190603 1541260
55 MacGregor JT Wehr CM Henika PR Shelby MD The in vivo erythrocyte micronucleus test: measurement at steady state increases assay efficiency and permits integration with toxicity studies. Fundam Appl Toxicol. 1990;14(3):513–522. http://dx.doi.org/10.1016/0272-0590(90)90255-I 2111256
56 Roe FJ Field WE Chronic toxicity of essential oils and certain other products of natural origin. Food Cosmet Toxicol. 1965;3(2):311–323. http://dx.doi.org/10.1016/S0015-6264(65)80090-6 5859246
57 Swenberg JA Alpha 2u-globulin nephropathy: review of the cellular and molecular mechanisms involved and their implications for human risk assessment. Environ Health Perspect. 1993;101 Suppl 6:39–44. http://dx.doi.org/10.1289/ehp.93101s639 7517351
58 Doi AM Hill G Seely J Hailey JR Kissling G Bucher JR α 2u-globulin nephropathy and renal tumors in national toxicology program studies. Toxicol Pathol. 2007;35(4):533–540. http://dx.doi.org/10.1080/01926230701338941 17562486
59 United States Environmental Protection Agency (USEPA). Alpha 2u-globulin: Association with chemically induced renal toxicity and neoplasia in the male rat. Washington, DC: U.S. Environmental Protection Agency, prepared for the Risk Assessment Forum; 1991. EPA/625/3-91/019F.
60 Intermational Agency for Research on Cancer (IARC). Species differences in thyroid, kidney and urinary bladder carcinogenesis: IARC Scientific Publications No. 147. Lyon, France: Intermational Agency for Research on Cancer (IARC); 1999.
61 Amacher DE Schomaker SJ Burkhardt JE The relationship among microsomal enzyme induction, liver weight and histological change in rat toxicology studies. Food Chem Toxicol. 1998;36(9-10):831–839. http://dx.doi.org/10.1016/S0278-6915(98)00066-0 9737431
62 Hashimoto M Davis DC Gillette JR Effect of different routes of administration of cedrene on hepatic drug metabolism. Biochem Pharmacol. 1972;21(10):1514–1517. http://dx.doi.org/10.1016/0006-2952(72)90377-2 5029428
63 Sabine JR Exposure to an environment containing the aromatic red cedar, Juniperus virginiana: procarcinogenic, enzyme-inducing and insecticidal effects. Toxicology. 1975;5(2):221–235. http://dx.doi.org/10.1016/0300-483X(75)90119-5 174251
64 Jeong H-U Kwon S-S Kong TY Kim JH Lee HS Inhibitory effects of cedrol, β-cedrene, and thujopsene on cytochrome P450 enzyme activities in human liver microsomes. J Toxicol Environ Health A. 2014;77(22-24):1522–1532. http://dx.doi.org/10.1080/15287394.2014.955906 25343299
65 Weiss G Goodnough LT Anemia of chronic disease. N Engl J Med. 2005;352(10):1011–1023. http://dx.doi.org/10.1056/NEJMra041809 15758012
66 Everds NE Snyder PW Bailey KL Bolon B Creasy DM Foley GL Rosol TJ Sellers T Interpreting stress responses during routine toxicity studies: a review of the biology, impact, and assessment. Toxicol Pathol. 2013;41(4):560–614. http://dx.doi.org/10.1177/0192623312466452 23475558
67 Bellanato J Hidalgo A Infrared analysis of essential oils. London, UK: Heyden and Son Limited; 1971.
68 Sigma-Aldrich Chemical Company. The Aldrich library of infrared spectra: Vol 3, spectrum 66B. Milwaukee, WI: Sigma-Aldrich Chemical Company; 1981.