# Discussion

Virginia cedarwood oil has widespread use as a fragrance in personal and household products and as an active ingredient in the cedar balls and wooden blocks that are used as moth and bug repellants; the alcohols and terpenes from cedarwood oil have been considered Generally Recognized As Safe by the FDA as a food additive.^25,6,15^ As a result of increasing widespread human exposure and the lack of toxicity data, cedarwood oil was nominated by the National Cancer Institute for subchronic toxicity studies. Given the widespread use and large production volume of Virginia cedarwood oil (hereafter referred to as cedarwood oil), this cedarwood oil product was chosen as the test article for the studies in this report. The dermal route of exposure was chosen for the current studies based on the pattern of use in humans. Due to a lack of information on the levels of exposure in the literature, the concentrations selected for these studies were untreated control; 0% (vehicle control), 6.25%, 12.5%, 25%, or 50% (with 95% ethanol as the vehicle); and 100% (neat; the highest dose possible) cedarwood oil. The untreated control group was included in addition to the 0% vehicle control group, because the 100% cedarwood oil dosing solution contained no dosing vehicle (i.e., 95% ethanol). These applied concentrations corresponded to approximately 31.25 to 500 mg cedarwood oil/kg body weight in the rat and 125 to 2,000 mg/kg in the mouse. The main toxicity targets of cedarwood oil were the skin at the site of application and the kidney.

Dosing with cedarwood oil for 3 months in rats resulted in severe skin lesions (e.g., irritation, thickening, and ulceration of the skin) at the site of application in all dosed groups, which resulted in the early termination of two male rats in the 100% group. Due to reduced survival of mice in the 100% groups and the increased incidences and severities of skin lesions at lower doses, mice appeared to be more sensitive to dermal application of cedarwood oil than rats. Though the mice appear to be more sensitive, this could be attributed to the application of a greater amount of the test article, resulting in an overall higher equivalent mg/kg dose. There was evidence of general treatment-related increases in absolute and/or relative kidney weights in the male rats. Additionally, there were general treatment-related decreases in absolute thymus weights in both sexes of both species.

During the 3-month studies, the most significant toxic response to cedarwood oil administration occurred in the skin at the site of application in rats and mice. In general, this was accompanied by microscopic lesions of minimal to moderate severities in the rats and moderate to marked severities in the mice and included epidermal hyperplasia, hyperkeratosis, and ulceration. There were also significant increases in the incidences of hair follicle and sebaceous gland hyperplasia in male and female rats in most dosed groups, and considerable increases in the incidences and severities of the lesions in mice. Incidences of chronic active inflammation increased with increasing dose in the rats and were graded minimal to mild; incidences and severities of this lesion were greater in mice than rats. Chronic active inflammation was characterized by the infiltration of neutrophils and macrophages into the dermis with occasional extensions into the hypodermis. Most data reported from studies of skin irritation or sensitization resulting from cedarwood oil exposure are conflicting and limited because of the low number of subjects evaluated. The majority of the studies testing the potential for skin irritation or sensitivity following acute exposure to cedarwood oil used low concentrations and did not find sensitization or irritation in the small numbers of animals or humans tested.^30,11,56^ However, some of the studies did show that application of full strength cedarwood oil to rabbits for 24 hours induced moderate skin irritation.^11^ In humans, a study examining the skin irritation potential of cedarwood oil was performed over a 24- to 72-hour period and found no evidence of skin irritation in the following groups: 0.2% (148 subjects), 2.5% (30 subjects), or 20% (29 subjects).^32^

In the current studies, there were multiple indications of renal injury following dermal administration of cedarwood oil. The 3-month dermal treatment resulted in dose-dependent increases in relative kidney weights in both male and female rats. In male rats, administration of cedarwood oil resulted in the accumulation of hyaline droplets within the epithelial cells of the proximal tubules; incidences and severities of the lesion increased with increasing dose. Exacerbation of the dose-related formation and accumulation of these hyaline droplets was further verified by Mallory-Heidenhain staining. Additionally, there were pronounced granular casts within the luminal compartment of the renal tubules along the corticomedullary junction. The granular casts formed as a result of the accumulation of cellular debris within the tubules, and their presence indicated prior injury and death of the renal tubule epithelium. There was also evidence of significant renal tubule degeneration in male rats at the higher doses, which was characterized by cellular swelling, mild hypereosinophilia, and sloughing of the renal cortical tubule epithelial cells. Although the incidences of renal tubule degeneration increased with increasing dose, the lesions were subtle and given minimal severity grades in all groups. Spontaneous chronic progressive nephropathy occurs commonly in the kidneys of male, but not female, F344/N rats, and evidence of treatment-related nephropathy can be established if there is a dose-dependent increase in the severities of the lesion. In the current study, nephropathy was characterized by the presence of renal tubule epithelial regeneration foci that increased in severity in the 50% and 100% groups.

The incidences of these nonneoplastic kidney lesions may be related to α2u-globulin nephropathy, a renal syndrome that specifically occurs in male F344/N rats and has been linked to the occurrence of tubular neoplasms.^57^ This syndrome is characterized by several key histologic events that are thought to be secondary to toxicity, and include multifocal tubule regeneration, tubule protein casts, thickening of the tubule and glomerular basement membrane, interstitial fibrosis, and chronic inflammatory cell infiltration.^58^ This mechanism has been demonstrated in 3-month studies with several structurally diverse chemicals, including α-pinene, decalin, and propylene glycol mono-t-butyl ether^58^; the incidences and severities of these histologic lesions following cedarwood oil exposure were not as marked as with these other compounds. The lesions observed in the current study meet some of the criteria for α2u-globulin-associated nephropathy in male rat renal carcinogenesis established by USEPA^59^ and the International Agency for Research on Cancer.^60^ However, some of the other criteria used by these Agencies, such as measurement of α2u-globulin within the hyaline droplets, were not investigated in the current study. Though the possibility of an α2u-globulin mechanism of renal toxicity exists, the occurrence of these effects was limited to the two highest doses (50% and 100%) tested in the current study. There were also increases in kidney weights in female mice, indicating the possibility for another mechanism of toxicity.

In the current studies, there was some indication of a potential liver effect from administration of cedarwood oil in both rats and mice. Significant liver effects were more pronounced in mice, which could be attributed to the mice receiving a higher dose on a mg/kg basis. There were significant increases in relative liver weights at higher doses in male and female rats, whereas all dosed groups of mice had increases in relative liver weights. Chemical-induced increased liver weight has been associated with induction of drug-metabolizing enzymes, and is not uncommon in toxicologic studies. Drug-metabolizing enzymes such as the cytochrome P450s are often associated with liver weight increases greater than 20% and with evidence of hepatocellular hypertrophy, although hypertrophy may not always be present.^61^ Cedrene, a major chemical constituent of cedarwood oil, has been shown in vivo to produce substantive increases in ethylmorphine N-demethylase activities and cytochrome P450 content in comparison to controls, with minimal differences due to routes of administration.^62^ Another study exhibited that animals housed on cedar shavings had increased incidences of spontaneous tumors of the liver as well as a highly significant reduction in barbiturate sleeping time, an indication of the induction of liver drug metabolizing enzymes including cytochrome P450.^63^ Conversely, in more recent in vitro studies, the constituents cedrol, β-cedrene, and thujopsene were found to inhibit the activities of CYP2B6 and CYP3A4 in human liver microsomes.^64^ Additionally, in the current study, microscopic evaluation of hepatocytes within male and female mice revealed increased incidences and severities of glycogen depletion at all doses greater than 6.25% that generally increased with increasing dose. Hepatocyte glycogen depletion was characterized by the lack of large, coalescing, perinuclear clear spaces within the hepatocyte cytoplasm in the dosed animals compared to the controls. Glycogen storage in hepatocytes acts as a cellular energy reserve, and in fasting conditions, these glycogen stores may be depleted. Hepatocyte glycogen depletion in the mice administered cedarwood oil may be related to the decrease in body weight and reduced food intake, which is supported by the inverse relationship between the decreased body weights and depletion of their glycogen stores.

Significantly increased incidences of nonneoplastic lesions occurred in the bone marrow, lymph nodes, and spleen of most dosed groups of mice. In the bone marrow, this occurred in the incidences of myeloid cell hyperplasia in all dosed groups of mice, except for 6.25% females. Lymphoid hyperplasia occurred in both the mandibular and axillary lymph nodes, however, lymphoid hyperplasia in the axillary lymph nodes occurred only in the 100% group. Significantly increased incidences and severities of splenic hematopoietic cell proliferation occurred in all dosed groups of mice. These effects are indicative of an inflammatory reaction to the dermal application of cedarwood oil and are considered to be secondary to the severe skin lesions at the application site. This is supported by alterations in clinical pathology parameters, which included increases in leukon alongside decreases in erythron. This increase in the total and differential white blood cell counts (specifically the neutrophils) was consistent with an inflammatory leukogram secondary to the dermal irritation and inflammation. The decreased erythron with no alterations in mean cell volume or mean cell hemoglobin concentration is consistent with an anemia of chronic disease also secondary to the inflammation at the site of application.^65^

Dermal exposure to cedarwood oil resulted in decreases in the absolute and relative thymus weights of rats and mice. On a mg/kg body weight basis, the mice received doses of cedarwood oil that were approximately four times higher than the rats, which could be why the mice had higher incidences of decreased thymus weights across more doses than did the rats. In mice, significant decreases in absolute thymus weights were observed in 25% and 50% males and 12.5% or greater females compared to the vehicle controls. Thymus weight decreases in the male mice were accompanied by thymic atrophy, which consisted of thymocyte depletion in the cortex of the thymus. In rats, absolute thymus weights were significantly decreased in 25% and 100% males and 100% females. The thymus is the most sensitive of the lymphoid organs in response to stress, and stress-related decreases in weight due to lymphocyte depletion may be seen within hours of exposure.^66^ The thymus effects observed in the current studies in rats and mice are consistent with stress-related organ effects that are a common secondary finding in toxicity studies, and can show dose proportionality.

Cedarwood oil was not found to be mutagenic in any of the Salmonella typhimurium strains tested in vitro or in an in vivo micronucleus test in the peripheral blood of male mice. However, increased micronucleated erythrocyte counts were judged to be equivocal in female mice following 3 months of dermal exposure to cedarwood oil, due to a significant positive trend in the absence of significant dosed group increases relative to controls. In addition, there was no evidence of treatment-related alterations within the micronucleated reticulocyte population in either male or female mice, suggesting that bone marrow toxicity is not induced by dermal application of cedarwood oil.

Under the conditions of the 3-month dermal studies with Virginia cedarwood oil, there were treatment-related lesions in male and female rats and mice. Skin (at the site of application) and kidney were the major targets from administration of cedarwood oil in both rats and mice. Additionally, the liver and the thymus were considered secondary targets of cedarwood oil administration as a result of the skin effects at the site of application in both rats and mice. The most sensitive measures of cedarwood oil administration in each species and sex were: increased incidences of skin (site of application) lesions in male [lowest-observed-effect-level (LOEL) = 12.5%; approximately equivalent to 62.5 mg/kg] and female (LOEL = 6.25%; approximately equivalent to 31.25 mg/kg) rats and increased incidences of skin (site of application) lesions (LOEL = 6.25%; approximately equivalent to 124 mg/kg) in male and female mice.