# Results

## Three-month Study in Rats

With the exceptions of two males in the 100% group, which were removed due to severe skin lesions, all rats survived to the end of the study (Table 2). Final mean body weights and body weight gains of 50% and 100% males and females were significantly less than those of their respective control groups and the mean body weight gain of male rats in the 25% group was significantly less than that of the vehicle control group (Table 2 and Figure 2). Test article-related clinical observations included irritation, thickening, and ulceration of the skin at the site of application in most males in the 25% or greater groups and most females in the 12.5% or greater groups.

Table 2 Survival and Body Weights of Rats in the Three-month Dermal Study of Cedarwood Oil^a^

Concentration (%) | Survival^b^ | Initial Body Weight (g) | Final Body Weight (g) | Change in Body Weight (g) | Final Weight Relative to Controls^c^ (%)
Male
Untreated Control | 10/10 | 113 ± 2 | 323 ± 4 | 209 ± 3
Vehicle Control | 10/10 | 114 ± 2 | 329 ± 4 | 215 ± 4
6.25 | 10/10 | 114 ± 2 | 318 ± 5 | 204 ± 4 | 97
12.5 | 10/10 | 113 ± 2 | 316 ± 6 | 203 ± 5 | 96
25 | 10/10 | 114 ± 2 | 308 ± 10 | 195 ± 8* | 94
50 | 10/10 | 113 ± 2 | 301 ± 8* | 188 ± 8** | 92
100 | 8/10^d^ | 115 ± 2 | 279 ± 7†† | 166 ± 7†† | 87
Female
Untreated Control | 10/10 | 102 ± 1 | 200 ± 4 | 98 ± 4
Vehicle Control | 10/10 | 103 ± 2 | 197 ± 2 | 94 ± 2
6.25 | 10/10 | 102 ± 2 | 199 ± 4 | 97 ± 3 | 101
12.5 | 10/10 | 103 ± 1 | 194 ± 5 | 91 ± 4 | 98
25 | 10/10 | 102 ± 1 | 193 ± 4 | 91 ± 3 | 98
50 | 10/10 | 102 ± 1 | 182 ± 4* | 80 ± 3** | 92
100 | 10/10 | 102 ± 2 | 179 ± 3†† | 78 ± 3†† | 90

* Significantly different (P ≤ 0.05) from the vehicle control group by Williams’ or Dunnett’s test.

** P ≤ 0.01.

†† Significantly different (P ≤ 0.01) from the untreated control group by a t-test.

^a^ Weights and weight changes are given as mean ± standard error.

^b^ Number of animals surviving at 14 weeks/number initially in group.

^c^ Dosed groups are compared to the vehicle control groups, except 100% groups are compared to the untreated control groups.

^e^ Week of deaths: 12.

Figure 2

Growth Curves for Rats Administered Cedarwood Oil Dermally for Three Months

The hematology data for rats are presented in Table B-1. There was a small (30% to 40%) increase in the total white blood cell counts of 50% females and the 100% groups of both sexes. The increased leukon was characterized most consistently by two-to three-fold increases in neutrophil counts, and to a lesser extent, increases in monocyte counts in the 100% male and female groups. Neutrophil counts were also minimally increased (30% to 40%) in the 50% male and female groups. A minimal decrease in erythron (5%) was evidenced by small decreases in the hematocrit value and hemoglobin concentration of 100% females and the erythrocyte count of 100% males.

There were no changes in the number of sperm or spermatids, sperm motility, or testis and epididymis weights of dosed males (Table D-1). There were no estrous cycle changes in dosed females (Table D-2, Table D-3; Figure D-1). Under the conditions of this study, cedarwood oil applied dermally did not exhibit the potential to be a reproductive toxicant in male or female F344/N rats.

Relative liver weights of males in the 50% and 100% groups, and absolute and relative liver weights of females in the 100% group were significantly greater than those in the respective control groups (Table 3 and Table C-1). The absolute kidney weight of 100% males and relative kidney weights of males in the 50% and 100% groups and females in the 25% or greater groups were significantly greater than those in the respective control groups. However, the kidney weight changes in females are most likely attributable to overall body weight changes. The absolute thymus weights of 25% and 100% males and the absolute and relative thymus weights of 100% females were significantly less than those in the respective control groups. The organ weight changes in the liver, kidney, and thymus were not accompanied by any significant histopathologic lesions.

Table 3 Organ Weights and Organ-Weight-to-Body-Weight Ratios for Rats in the Three-month Dermal Study of Cedarwood Oil^a^

| Untreated Control | Vehicle Control | 6.25% | 12.5% | 25% | 50% | 100%
Male
n | 10 | 10 | 10 | 10 | 10 | 10 | 8
Necropsy body wt | 323 ± 4 | 329 ± 4 | 318 ± 5 | 316 ± 6 | 308 ± 10 | 301 ± 8* | 279 ± 7††
R. Kidney
Absolute | 1.09 ± 0.02 | 1.15 ± 0.02† | 1.08 ± 0.03 | 1.10 ± 0.02 | 1.12 ± 0.04 | 1.19 ± 0.03 | 1.33 ± 0.05††
Relative | 3.37 ± 0.05 | 3.51 ± 0.04† | 3.40 ± 0.04 | 3.50 ± 0.07 | 3.63 ± 0.06 | 3.96 ± 0.08** | 4.77 ± 0.11††
Liver
Absolute | 12.42 ± 0.37 | 12.75 ± 0.26 | 12.91 ± 0.38 | 12.47 ± 0.31 | 12.60 ± 0.49 | 13.07 ± 0.37 | 13.43 ± 0.42
Relative | 38.55 ± 1.21 | 38.79 ± 0.58 | 40.58 ± 0.97 | 39.52 ± 0.75 | 40.89 ± 0.86 | 43.49 ± 0.84** | 48.18 ± 1.31††
Thymus
Absolute | 0.282 ± 0.013 | 0.282 ± 0.006 | 0.277 ± 0.008 | 0.280 ± 0.010 | 0.245 ± 0.011* | 0.271 ± 0.014 | 0.223 ± 0.016†
Relative | 0.875 ± 0.044 | 0.857 ± 0.014 | 0.870 ± 0.023 | 0.887 ± 0.033 | 0.798 ± 0.032 | 0.904 ± 0.049 | 0.797 ± 0.051
Female
Necropsy body wt | 200 ± 4 | 197 ± 2 | 199 ± 4 | 194 ± 5 | 193 ± 4 | 182 ± 4* | 179 ± 3††
R. Kidney
Absolute | 0.72 ± 0.01 | 0.71 ± 0.02 | 0.73 ± 0.02 | 0.71 ± 0.02 | 0.74 ± 0.02 | 0.70 ± 0.02 | 0.75 ± 0.01
Relative | 3.59 ± 0.07 | 3.59 ± 0.05 | 3.65 ± 0.04 | 3.63 ± 0.05 | 3.85 ± 0.06** | 3.86 ± 0.07** | 4.17 ± 0.09††
Liver
Absolute | 6.97 ± 0.18 | 7.02 ± 0.18 | 6.93 ± 0.23 | 7.10 ± 0.19 | 7.14 ± 0.18 | 6.80 ± 0.21 | 7.58 ± 0.13†
Relative | 34.94 ± 0.60 | 35.62 ± 0.79 | 34.74 ± 0.55 | 36.60 ± 0.62 | 36.98 ± 0.56 | 37.28 ± 0.56 | 42.30 ± 0.42††
Thymus
Absolute | 0.279 ± 0.016 | 0.240 ± 0.006† | 0.263 ± 0.012 | 0.245 ± 0.013 | 0.244 ± 0.008 | 0.225 ± 0.009 | 0.213 ± 0.009††
Relative | 1.395 ± 0.071 | 1.220 ± 0.030† | 1.320 ± 0.055 | 1.265 ± 0.064 | 1.262 ± 0.036 | 1.236 ± 0.046 | 1.189 ± 0.055††

* Significantly different (P ≤ 0.05) from the vehicle control group by Williams’ or Dunnett’s test.

** P ≤ 0.01.

† Significantly different (P ≤ 0.05) from the untreated control group by t-test.

†† P ≤ 0.01.

^a^ Organ weights (absolute weights) and body weights are given in grams; organ-weight-to-body-weight ratios (relative weights) are given as mg organ weight/g body weight (mean ± standard error).

Compared to those in the respective control groups, the incidences of several nonneoplastic lesions of the skin at the site of application were significantly increased in dosed groups of males and females (Table 4, Table A-1, Table A-2). The incidences of epidermal hyperplasia were significantly increased in 12.5% or greater males and all dosed groups of females. The incidences of epidermal hyperkeratosis and sebaceous gland hyperplasia were significantly increased in 25% or greater males and 12.5% or greater females. The incidences of epidermal ulcer were significantly increased in the 50% and 100% groups of males and females. The incidences of chronic active inflammation were significantly increased in 12.5% or greater males and females. The incidences of dermal fibrosis and hair follicle hyperplasia were significantly increased in 25% or greater males and females. Compared to normal skin (Figure 4 and Figure 5), epidermal hyperplasia was characterized by increased thickness of the epidermis due to an increase in the number of epithelial cell layers (Figure 6 and Figure 7). Hyperplasia frequently extended into and thickened the epithelium of the hair follicles and there were increased profiles of the hair follicle deep in the adjacent subcutaneous layers. Epithelial thicknesses of three, four, five, or greater than five layers of cells represented severity grades of minimal, mild, moderate, and marked, respectively. Epidermal hyperkeratosis generally accompanied hyperplasia and consisted of increased thickness of the epidermal keratin layer (Figure 8 and Figure 9). There were both ortho- and parakeratotic hyperkeratoses and the severities were determined by the number of increased cell layers compared to the respective controls. Frequently, there were dense accumulations of degenerate neutrophils within the keratin layers. Epidermal ulcer was characterized by focal, complete loss of the epidermis, often associated with necrosis of the underlying superficial dermis and filling of the epidermal defect with degenerate and/or necrotic cellular debris and degenerate inflammatory cells (Figure 10). The severity was based on the size of the ulcers and the number of affected areas in the skin section. Chronic active inflammation was characterized by infiltrates of neutrophils and macrophages in varying numbers (increasing with dose) throughout the dermis with infrequent extension into the hypodermis (Figure 11 and Figure 12). Occasionally, focal infiltrates of primarily neutrophils mixed with low numbers of macrophages were within the epidermis, hair follicles, and less frequently sebaceous glands. Dermal fibrosis was often associated with dermal inflammatory cell infiltrates and was characterized by increased amounts of collagenous/fibrous connective tissue in the dermis (Figure 13). Hair follicle hyperplasia was characterized by increased numbers of cross-sectional hair follicle profiles in association with thickening of the follicular epithelium that was an extension of the hyperplastic change that occurred in the epidermis (Figure 6 and Figure 7). Sebaceous gland hyperplasia was characterized by an increase in the size of the sebaceous glands due to increased number and size of the alveolar cells (Figure 6 and Figure 7).

Table 4 Incidences of Nonneoplastic Lesions of the Skin (Site of Application) in Rats in the Three-month Dermal Study of Cedarwood Oil

| Untreated Control | Vehicle Control | 6.25% | 12.5% | 25% | 50% | 100%
Male
Number Examined Microscopically | 10 | 10 | 10 | 10 | 10 | 10 | 10
Epidermis, Hyperplasia^a^ | 0 | 0 | 2 (1.0)^b^ | 4* (1.3) | 10** (2.0) | 10** (2.9) | 9†† (2.9)
Epidermis, Hyperkeratosis | 0 | 0 | 0 | 1 (1.0) | 7** (1.1) | 10** (1.6) | 10†† (3.0)
Sebaceous Gland, Hyperplasia | 0 | 0 | 0 | 0 | 9** (1.9) | 10** (2.8) | 10†† (3.0)
Epidermis, Ulcer | 0 | 0 | 0 | 1 (1.0) | 1 (3.0) | 7** (2.6) | 8†† (3.0)
Inflammation, Chronic Active | 0 | 0 | 1 (1.0) | 4* (1.0) | 9** (1.4) | 10** (2.3) | 10†† (2.7)
Dermis, Fibrosis | 0 | 0 | 0 | 0 | 7** (1.1) | 10** (2.4) | 10†† (2.4)
Hair Follicle, Hyperplasia | 0 | 0 | 0 | 0 | 9** (1.3) | 10** (2.0) | 9†† (1.8)
Female
Number Examined Microscopically | 10 | 10 | 10 | 10 | 10 | 10 | 10
Epidermis, Hyperplasia | 0 | 0 | 4* (1.0) | 7** (1.7) | 10** (2.1) | 10** (2.8) | 10†† (3.0)
Epidermis, Hyperkeratosis | 0 | 0 | 1 (1.0) | 5* (1.0) | 10** (1.2) | 10** (2.5) | 10†† (3.0)
Sebaceous Gland, Hyperplasia | 0 | 0 | 0 | 4* (1.0) | 9** (1.8) | 10** (2.9) | 10†† (3.0)
Epidermis, Ulcer | 0 | 0 | 0 | 1 (2.0) | 1 (3.0) | 4* (2.3) | 10†† (3.1)
Inflammation, Chronic Active | 0 | 0 | 0 | 7** (1.0) | 10** (1.2) | 10** (2.4) | 10†† (2.4)
Dermis, Fibrosis | 0 | 0 | 0 | 1 (1.0) | 7** (1.1) | 8** (1.8) | 10†† (2.1)
Hair Follicle, Hyperplasia | 0 | 0 | 0 | 1 (1.0) | 9** (1.7) | 10** (2.8) | 10†† (3.6)

* Significantly different (P ≤ 0.05) from the vehicle control group by the Fisher exact test.

** P ≤ 0.01.

†† Significantly different (P ≤ 0.01) from the untreated control group by the Fisher exact test.

^a^ Number of animals with lesion.

^b^ Average severity grade of lesions in affected animals: 1 = minimal, 2 = mild, 3 = moderate, 4 = marked.

Figure 4

Normal Skin (Site of Application) of a Vehicle Control Female F344/N Rat in the Three-month Dermal Study of Cedarwood Oil (H&E)

The epidermis (long arrows) is composed of a single layer of epithelial cells, and hair follicles are few and evenly spaced (short arrows).

Figure 5

Higher Magnification of Figure 4 (H&E)

Note the epidermis (long arrows) and hair follicles with associated sebaceous glands (short arrows).

Figure 6

Hyperplasia and Hyperkeratosis of the Epidermis (Site of Application) in the Skin of a Female F344/N Rat Administered 100% Cedarwood Oil Dermally for Three Months (H&E)

Compared to Figure 4, the epidermis (long arrows) and overlying keratin layer (arrowheads) are prominently thickened. Note that there are increased numbers of hair follicle profiles (hair follicle hyperplasia) within the dermis and subcutis (short arrows), and that the number and size of the associated sebaceous glands (curved arrows) are increased (sebaceous gland hyperplasia).

Figure 7

Higher Magnification of Figure 6 (H&E)

Note the thickened (hyperplastic) epidermis (long arrows), hyperkeratosis (arrowheads), and sebaceous gland hyperplasia (curved arrows).

Figure 8

Epidermal Hyperkeratosis in the Skin (Site of Application) of a Female F344/N Rat Administered 100% Cedarwood Oil Dermally for Three Months (H&E)

There is prominent thickening of the keratin layer (long arrows) that contains accumulations of degenerate neutrophils. Note that as an extension of epidermal hyperplasia, the epithelium of the hair follicles is also hyperplastic (short arrows). Note also the infiltrates of inflammatory cells in the dermis.

Figure 9

Higher Magnification of Figure 8 (H&E)

Note dense accumulations of degenerate neutrophils within the hyperplastic keratin layer (arrows) and infiltrates of inflammatory cells within the dermis (de).

Figure 10

Focal Epidermal Ulcer in the Skin (Site of Application) of a Female F344/N Rat Administered 100% Cedarwood Oil Dermally for Three Months (H&E)

Note focal complete loss of the epidermis (arrows) with accumulation of serum protein mixed with necrotic cellular debris at the site of ulceration. Note also epidermal, hair follicle, and sebaceous gland hyperplasia.

Figure 11

Marked Chronic Active Inflammation in the Skin (Site of Application) of a Female F344/N Rat Administered 100% Cedarwood Oil Dermally for Three Months (H&E)

Note a mixed inflammatory cell infiltrate within the dermis (arrows) and dense accumulation of degenerate neutrophils within the thickened keratin layer.

Figure 12

Higher Magnification of Figure 11 (H&E)

Note degenerate neutrophils within the hyperplastic keratin layer (arrows) and infiltrates of inflammatory cells within the dermis (de).

Figure 13

Dermal Fibrosis in the Skin (Site of Application) of a Female F344/N Rat Administered 100% Cedarwood Oil Dermally for Three Months (H&E)

Note the fibrotic tissue within the papillary dermis (arrows).

In the kidney, the incidences of renal tubule degeneration were significantly increased in 50% and 100% males compared to those in the respective control groups (Table 5 and Table A-1). In addition, the incidences of renal tubule granular casts and hyaline droplet accumulation were significantly increased in males in the 25% or greater groups compared to those in the respective control groups; the severity of these lesions increased with increasing dose. The severity of nephropathy in 50% and 100% males was mild compared to minimal in both control groups and the remaining dose groups. Renal tubule degeneration was a subtle lesion graded as minimal in all dose groups and was characterized by cell swelling, mild hypereosinophilia and sloughing of the tubule epithelial cells. Rare, sloughed degenerate epithelial cells were present in the lumen of the renal cortical tubules, of which the proximal convoluted tubules were primarily affected and the distal tubules were affected to a lesser extent. The sloughed cells were shrunken and had scant eosinophilic cytoplasm and condensed dark nuclei (Figure 14). Renal tubule granular casts consisted of variable dilation of the renal tubules along the corticomedullary junction with a lightly eosinophilic, granular material and occasionally mixed with cellular debris (Figure 15 and Figure 16). The severity of granular casts was graded as minimal if there were 10 or fewer casts in the transverse section of the kidney and 20 or fewer in the longitudinal section; mild if there were 11 to 20 casts in the transverse section and 21 to 49 in the longitudinal section; moderate if there were 21 to 49 casts in the transverse section and 50 or more in the longitudinal section; and marked when there were 50 or more casts each in the transverse and longitudinal sections. Hyaline droplet accumulation was characterized by variable amounts of granular to globular, intracytoplasmic eosinophilic, proteinaceous material within the epithelial cells of the proximal tubules. Severity of hyaline droplet accumulation was graded according to the character and amount of accumulated material in the tubule epithelial cells. In controls and males dosed with 6.25% or 12.5% cedarwood oil, the granules were fine and round (Figure 17 and Figure 18), whereas in males dosed with 50% or 100% cedarwood oil, the material appeared as larger, variable-sized round to irregular globules (Figure 19 and Figure 20). Nephropathy consisted of a few scattered renal tubule epithelial cell regeneration foci. The affected tubules had increased numbers of tubular epithelial cells that had basophilic cytoplasm compared to the eosinophilic cytoplasm of unaffected tubules. The basement membrane surrounding these tubules tended to be slightly thickened.

Table 5 Incidences of Selected Nonneoplastic Lesions in Rats in the Three-month Dermal Study of Cedarwood Oil

| Untreated Control | Vehicle Control | 6.25% | 12.5% | 25% | 50% | 100%
Male
Kidney^a^ | 10 | 10 | 10 | 10 | 10 | 10 | 10
Renal Tubule, Degeneration^b^ | 2 (1.0)^c^ | 4 (1.0) | 5 (1.0) | 6 (1.0) | 7 (1.0) | 10** (1.0) | 10†† (1.0)
Renal Tubule, Casts Granular | 0 | 0 | 0 | 0 | 5* (1.0) | 10** (1.6) | 10†† (3.5)
Accumulation, Hyaline Droplet | 0 | 0 | 0 | 0 | 10** (1.1) | 10** (1.9) | 10†† (3.0)
Nephropathy | 10 (1.0) | 10 (1.0) | 10 (1.0) | 10 (1.0) | 10 (1.0) | 10 (2.0) | 10 (2.0)
Bone Marrow | 10 | 10 | 10 | 10 | 10 | 10 | 10
Hyperplasia | 0 | 0 | 0 | 0 | 0 | 1 (1.0) | 7†† (1.1)
Female
Bone Marrow | 10 | 10 | 9 | 10 | 10 | 10 | 10
Hyperplasia | 0 | 0 | 0 | 0 | 2 (1.0) | 2 (1.0) | 7†† (1.0)

* Significantly different (P ≤ 0.05) from the vehicle control group by the Fisher exact test.

** P ≤ 0.01.

†† Significantly different (P ≤ 0.01) from the untreated control group by the Fisher exact test.

^a^ Number of animals with tissue examined microscopically.

^b^ Number of animals with lesion.

^c^ Average severity grade of lesions in affected animals: 1 = minimal, 2 = mild, 3 = moderate, 4 = marked.

Figure 14

Renal Tubule Degeneration in the Kidney of a Male F344/N Rat Administered 100% Cedarwood Oil Dermally for Three Months (H&E)

Note sloughed, shrunken, degenerate epithelial cells within the lumen of a renal tubule (arrows).

Figure 15

Granular Casts in the Kidney of a Male F344/N Rat Administered 100% Cedarwood Oil Dermally for Three Months (H&E)

The renal tubules along the corticomedullary junction (arrows) are occluded and distended by eosinophilic, granular material (casts).

Figure 16

Higher Magnification of Figure 15 Showing Several Renal Tubules that are Occluded and Distended by Eosinophilic, Granular Casts (Asterisks) (H&E)

Figure 17

Normal Kidney of a Vehicle Control Male F344/N Rat in the Three-month Dermal Study of Cedarwood Oil Showing Uniformly Fine, Eosinophilic (Hyaline) Droplets (Arrows) within the Cytoplasm of Several Renal Tubule Epithelial Cells (H&E)

Figure 18

Normal Kidney of a Vehicle Control Male F344/N Rat in the Three-month Dermal Study of Cedarwood Oil Stained with the Mallory-Heidenhain Stain (Mallory-Heidenhain)

This special stain for protein highlights the morphology of the fine, eosinophilic (hyaline) droplets (arrows) within the cytoplasm of several renal tubule epithelial cells.

Figure 19

Kidney of a Male F344/N Rat Administered 100% Cedarwood Oil Dermally for Three Months (H&E)

Compared to Figure 17, there are larger, variable-sized, round to irregular eosinophilic (hyaline) droplets (arrows) within the cytoplasm of several renal tubule epithelial cells.

Figure 20

Kidney of a Male F344/N Rat Administered 100% Cedarwood Oil Dermally for Three Months Stained with the Mallory-Heidenhain Stain for Protein (Mallory-Heidenhain)

Compared to Figure 18, note the morphology of the larger, variable-sized, round to irregular eosinophilic (hyaline) droplets (arrows) within the cytoplasm of several renal tubule epithelial cells.

In the bone marrow, the incidences of hyperplasia were significantly increased in 100% males and females compared to those in the untreated control groups (Table 5, Table A-1, and Table A-2). Bone marrow hyperplasia was characterized by increased numbers of hematopoietic cells (primarily granulocytes) within the marrow cavity and was considered to be secondary to the lesions observed in the skin at the site of application.

## Three-month Study in Mice

Due to the severities of lesions in the skin at the site of application, all males and females in the 100% groups, one male and one female each in the 50% groups, and one male in the 12.5% group were euthanized during weeks 10, 11, and 12, respectively; all other male and female mice survived to the end of the study (Table 6). The final mean body weights of 25% and 50% males and 12.5% or greater females and the mean body weight gains of 12.5% or greater males and females were significantly less than those of the vehicle control groups (Table 6 and Figure 3). Test article-related clinical observations included irritation, thickening, and ulceration of the skin at the site of application in most of the dosed mice.

Table 6 Survival and Body Weights of Mice in the Three-month Dermal Study of Cedarwood Oil^a^

Concentration (%) | Survival^b^ | Initial Body Weight (g) | Final Body Weight (g) | Change in Body Weight (g) | Final Weight Relative to Controls (%)
Male
Untreated Control | 10/10 | 21.9 ± 0.4 | 39.7 ± 1.3 | 17.8 ± 1.1
Vehicle Control | 10/10 | 21.7 ± 0.3 | 36.9 ± 0.8 | 15.2 ± 0.6
6.25 | 10/10 | 21.7 ± 0.3 | 36.0 ± 0.6 | 14.4 ± 0.5 | 98
12.5 | 9/10^c^ | 22.1 ± 0.4 | 35.1 ± 1.1 | 13.1 ± 0.9* | 95
25 | 10/10 | 22.1 ± 0.5 | 33.1 ± 0.9** | 11.0 ± 0.7** | 90
50 | 9/10^d^ | 22.1 ± 0.4 | 31.9 ± 0.7** | 9.7 ± 0.6** | 86
100 | 0/10^e^ | – | – | – | –
Female
Untreated Control | 10/10 | 18.1 ± 0.2 | 34.9 ± 0.9 | 16.8 ± 0.9
Vehicle Control | 10/10 | 17.8 ± 0.3 | 34.7 ± 1.1 | 16.9 ± 1.0
6.25 | 10/10 | 18.0 ± 0.4 | 34.0 ± 0.9 | 16.1 ± 0.7 | 98
12.5 | 10/10 | 17.9 ± 0.2 | 30.5 ± 0.7** | 12.6 ± 0.7** | 88
25 | 10/10 | 17.8 ± 0.5 | 28.1 ± 0.6** | 10.3 ± 0.6** | 81
50 | 9/10^d^ | 18.3 ± 0.4 | 30.2 ± 0.4** | 11.9 ± 0.5** | 87
100 | 0/10^e^ | – | – | – | –

* Significantly different (P ≤ 0.05) from the vehicle control group by Williams’ test.

** P ≤ 0.01.

^a^ Weights and weight changes are given as mean ± standard error.

^b^ Number of animals surviving at 14 weeks/number initially in group.

^c^ Week of death: 12.

^d^ Week of death: 11.

^e^ Due to the severity of skin lesions, all 100% mice were euthanized during week 10.

Figure 3

Growth Curves for Mice Administered Cedarwood Oil Dermally for Three Months

The hematology data for mice are presented in Table B-2. Similar to the rat study, increases in total and differential white blood cell counts occurred. The leukon changes were characterized primarily by small (20% to 30%) increases in the total white blood cell counts of 25% and 50% females and two- to threefold increases in neutrophil counts in 25% female and 50% male and female groups. Also similar to the rat study was the presence of a decreased erythron. In the mice, however, the evidence was more consistent and widespread involving decreases of all three estimators of the circulating red cell mass (i.e., the hematocrit values, hemoglobin concentrations, and erythrocyte counts) in 12.5% males and 25% and 50% males and females. In addition, the severity of the erythron decrease (approximately 13%) in the 50% groups was more than twice that of the 100% groups (approximately 5%).

There were no changes in the number of sperm and spermatids, sperm motility, or testis and epididymis weights of dosed males (Table D-4). There were no estrous cycle changes in dosed females (Table D-5 and Table D-6; Figure D-2). Under the conditions of this study, cedarwood oil applied dermally did not exhibit the potential to be a reproductive toxicant in male or female B6C3F1/N mice.

Absolute liver weights of 50% males and females and relative liver weights of all dosed groups of males and females were significantly greater than those of the vehicle control groups (Table 7 and Table C-2). The absolute kidney weight of 50% females and relative kidney weights of 50% males and 12.5% or greater females were significantly greater than those of the vehicle control groups. However, the kidney weight changes in males are most likely attributable to overall body weight changes. Absolute thymus weights of 25% and 50% males and 12.5% or greater females were significantly less than those of the vehicle controls.

Table 7 Organ Weights and Organ-Weight-to-Body-Weight Ratios for Mice in the Three-month Dermal Study of Cedarwood Oil^a,b^

| Vehicle Control | 6.25% | 12.5% | 25% | 50%
n | 10 | 10 | 9 | 10 | 9
Male
Necropsy body wt | 36.9 ± 0.8 | 36.0 ± 0.6 | 35.1 ± 1.1 | 33.1 ± 0.9** | 31.9 ± 0.7**
R. Kidney
Absolute | 0.29 ± 0.01 | 0.29 ± 0.01 | 0.30 ± 0.01 | 0.28 ± 0.01 | 0.29 ± 0.01
Relative | 7.94 ± 0.12 | 8.16 ± 0.22 | 8.51 ± 0.21 | 8.35 ± 0.26 | 9.03 ± 0.14**
Liver
Absolute | 1.66 ± 0.04 | 1.76 ± 0.04 | 1.81 ± 0.05 | 1.77 ± 0.06 | 1.98 ± 0.04**
Relative | 45.06 ± 0.58 | 48.85 ± 1.18** | 51.51 ± 0.57** | 53.44 ± 1.06** | 62.12 ± 1.21**
Thymus
Absolute | 0.048 ± 0.004 | 0.050 ± 0.002 | 0.044 ± 0.003 | 0.040 ± 0.001* | 0.038 ± 0.002*
Relative | 1.306 ± 0.077 | 1.374 ± 0.057 | 1.232 ± 0.063 | 1.224 ± 0.041 | 1.205 ± 0.073
Female
Necropsy body wt | 34.7 ± 1.1 | 34.0 ± 0.9 | 30.5 ± 0.7** | 28.1 ± 0.6** | 30.2 ± 0.4**
R. Kidney
Absolute | 0.19 ± 0.01 | 0.20 ± 0.00 | 0.20 ± 0.00 | 0.20 ± 0.00 | 0.24 ± 0.01**
Relative | 5.58 ± 0.18 | 5.94 ± 0.13 | 6.67 ± 0.18** | 7.07 ± 0.15** | 7.86 ± 0.16**
Liver
Absolute | 1.58 ± 0.05 | 1.65 ± 0.02 | 1.62 ± 0.03 | 1.60 ± 0.04 | 2.05 ± 0.05**
Relative | 45.61 ± 0.79 | 48.75 ± 0.79* | 53.24 ± 0.77** | 57.10 ± 1.02** | 67.80 ± 0.82**
Thymus
Absolute | 0.061 ± 0.004 | 0.068 ± 0.004 | 0.051 ± 0.002* | 0.051 ± 0.003* | 0.045 ± 0.002**
Relative | 1.759 ± 0.087 | 1.990 ± 0.096 | 1.679 ± 0.063 | 1.802 ± 0.076 | 1.506 ± 0.070

* Significantly different (P ≤ 0.05) from the vehicle control group by Williams’ or Dunnett’s test.

** P ≤ 0.01.

^a^ Organ weights (absolute weights) and body weights are given in grams; organ-weight-to-body-weight ratios (relative weights) are given as mg organ weight/g body weight (mean ± standard error).

^b^ Due to the severity of skin lesions, all 100% mice were euthanized during week 10.

The incidences of epidermal hyperplasia, hyperkeratosis, and ulcer and chronic active inflammation, dermal fibrosis, hair follicle hyperplasia, and sebaceous gland hyperplasia were significantly increased in most groups of males and females (Table 8, Table A-3, and Table A-4).

Table 8 Incidences of Nonneoplastic Lesions of the Skin (Site of Application) in Mice in the Three-month Dermal Study of Cedarwood Oil

| Untreated Control | Vehicle Control | 6.25% | 12.5% | 25% | 50% | 100%^a^
Male
Number Examined Microscopically | 10 | 9 | 10 | 10 | 10 | 10 | 10
Epidermis, Hyperplasia^b^ | 0 | 0 | 10** (2.6)^c^ | 10** (3.0) | 10** (3.0) | 10** (3.0) | 10†† (3.0)
Epidermis, Hyperkeratosis | 0 | 0 | 7** (2.1) | 10** (2.9) | 10** (3.0) | 10** (2.9) | 10†† (2.9)
Epidermis, Ulcer | 0 | 0 | 2 (4.0) | 8** (4.0) | 10** (3.8) | 9** (3.7) | 10†† (3.9)
Inflammation, Chronic Active | 0 | 0 | 10** (2.4) | 10** (3.0) | 10** (3.0) | 10** (3.0) | 10†† (3.2)
Dermis, Fibrosis | 0 | 0 | 3 (2.7) | 10** (3.0) | 10** (3.0) | 10** (3.0) | 10†† (3.0)
Hair Follicle, Hyperplasia | 0 | 0 | 10** (2.6) | 10** (3.0) | 10** (3.0) | 10** (3.0) | 10†† (3.0)
Sebaceous Gland, Hyperplasia | 0 | 0 | 10** (1.3) | 10** (2.3) | 10** (2.6) | 10** (2.3) | 10†† (2.0)
Female
Number Examined Microscopically | 10 | 10 | 10 | 10 | 10 | 10 | 10
Epidermis, Hyperplasia | 0 | 0 | 10** (2.1) | 10** (3.0) | 10** (3.0) | 10** (3.0) | 10†† (3.0)
Epidermis, Hyperkeratosis | 0 | 0 | 2 (1.5) | 10** (2.7) | 10** (3.0) | 10** (3.0) | 10†† (3.0)
Epidermis, Ulcer | 0 | 0 | 2 (3.0) | 6** (3.7) | 9** (4.0) | 10** (4.0) | 10†† (4.0)
Inflammation, Chronic Active | 0 | 0 | 10** (2.2) | 10** (3.0) | 10** (3.0) | 10** (3.0) | 10†† (3.0)
Dermis, Fibrosis | 0 | 0 | 2 (1.0) | 10** (2.9) | 10** (3.0) | 10** (3.0) | 10†† (3.0)
Hair Follicle, Hyperplasia | 0 | 0 | 3 (2.3) | 10** (3.0) | 10** (3.0) | 10** (3.0) | 10†† (3.0)
Sebaceous Gland, Hyperplasia | 1 (1.0) | 0 | 4* (1.3) | 10** (2.0) | 10** (2.2) | 10** (2.0) | 10†† (2.2)

* Significantly different (P ≤ 0.05) from the vehicle control group by the Fisher exact test.

** P ≤ 0.01.

†† Significantly different (P ≤ 0.01) from the untreated control group by the Fisher exact test.

^a^ Due to the severity of skin lesions, all 100% mice were euthanized during week 10.

^b^ Number of animals with lesion.

^c^ Average severity grade of lesions in affected animals: 1 = minimal, 2 = mild, 3 = moderate, 4 = marked.

In general, the site of application lesions that occurred in mice were morphologically similar to those observed in the rat study. Hair follicle hyperplasia was characterized by increased numbers of cross-sectional hair follicle profiles in association with thickening of the follicular epithelium that was an extension of the hyperplastic change that occurred in the epidermis. The associated sebaceous glands were variably enlarged due to increases in size and numbers of alveolar cells (sebaceous gland hyperplasia).

In the liver, the incidences of hepatocyte glycogen depletion were significantly increased in males and females in the 12.5% or greater groups compared to those in the respective control groups (Table 9, Table A-3, and Table A-4). The large, coalescing, perinuclear clear spaces (consistent with glycogen accumulation) present in the cytoplasm of hepatocytes of the controls were absent from the cytoplasm of the hepatocytes of dosed mice having the lesion. The cytoplasm of hepatocytes in the dosed mice appeared homogeneously eosinophilic or granular and contained basophilic floccular material. This was especially prominent in the 100% groups. With decreasing dose, the cytoplasm of hepatocytes appeared similar to that of the 100% groups although the clear cytoplasmic spaces were increasingly apparent but not as prominent or frequent as those in the control groups.

Table 9 Incidences of Selected Nonneoplastic Lesions in Mice in the Three-month Dermal Study of Cedarwood Oil

| Untreated Control | Vehicle Control | 6.25% | 12.5% | 25% | 50% | 100%^a^
Male
Liver^b^ | 10 | 10 | 10 | 10 | 10 | 10 | 10
Hepatocyte, Depletion Glycogen^c^ | 0 | 0 | 0 | 6** (1.8)^d^ | 9** (2.2) | 10** (3.0) | 10†† (3.0)
Bone Marrow | 10 | 10 | 10 | 10 | 10 | 10 | 10
Myeloid Cell, Hyperplasia | 0 | 0 | 5* (1.0) | 10** (1.6) | 10** (2.1) | 10** (2.8) | 10†† (4.0)
Spleen | 10 | 10 | 10 | 10 | 10 | 10 | 10
Hematopoietic Cell Proliferation | 0 | 0 | 6** (2.0) | 10** (2.3) | 10** (2.5) | 10** (3.0) | 10†† (2.9)
Lymph Node, Mandibular | 10 | 10 | 10 | 10 | 9 | 10 | 10
Hyperplasia, Lymphoid | 0 | 0 | 1 (3.0) | 6** (3.0) | 5* (2.6) | 9** (3.2) | 8†† (3.4)
Lymph Node | –^e^ | – | – | – | – | – | 9
Axillary, Hyperplasia, Lymphoid | – | – | – | – | – | – | 9 (3.9)
Thymus | 10 | 10 | 10 | 10 | 10 | 10 | 10
Atrophy | 0 | 0 | 0 | 0 | 5* (1.8) | 10** (1.7) | 10†† (1.8)
Kidney | 10 | 10 | 10 | 10 | 10 | 10 | 10
Nephropathy | 0 | 2 (1.0) | 0 | 1 (1.0) | 2 (1.0) | 3 (1.3) | 5† (1.0)
Female
Liver | 10 | 10 | 10 | 10 | 10 | 10 | 10
Hepatocyte, Depletion Glycogen | 0 | 0 | 0 | 5* (1.4) | 9** (2.1) | 10** (2.5) | 10†† (3.5)
Bone Marrow | 10 | 10 | 10 | 10 | 10 | 10 | 10
Myeloid Cell, Hyperplasia | 0 | 0 | 2 (1.5) | 9** (1.4) | 10** (3.0) | 10** (3.0) | 10†† (4.0)
Spleen | 10 | 10 | 10 | 10 | 10 | 10 | 10
Hematopoietic Cell Proliferation | 4 (2.0) | 2 (2.0) | 9** (2.1) | 10** (2.7) | 10** (2.6) | 10** (3.0) | 10†† (3.0)
Lymph Node, Mandibular | 10 | 10 | 10 | 10 | 10 | 10 | 10
Hyperplasia, Lymphoid | 0 | 1 (3.0) | 6* (2.7) | 6* (3.0) | 5 (3.6) | 6* (3.5) | 10†† (3.4)
Lymph Node | – | – | – | – | 1 | 2 | 10
Axillary, Hyperplasia, Lymphoid | – | – | – | – | 0 | 1 (4.0) | 10 (3.6)

* Significantly different (P ≤ 0.05) from the vehicle control group by the Fisher exact test.

** P ≤ 0.01.

† Significantly different (P ≤ 0.05) from the untreated control group by the Fisher exact test.

†† P ≤ 0.01.

^a^ Due to the severity of skin lesions, all 100% mice were euthanized during week 10.

^b^ Number of animals with tissue examined microscopically.

^c^ Number of animals with lesion.

^d^ Average severity grade of lesions in affected animals: 1 = minimal, 2 = mild, 3 = moderate, 4 = marked.

^e^ Tissue was not assessed in this group; the axillary lymph node is not a protocol required tissue and is collected and evaluated microscopically only when grossly abnormal.

Compared to incidences in the respective control groups, the incidences of bone marrow myeloid cell hyperplasia were significantly increased in all dosed groups of males and females (except 6.25% females) and the incidences of hematopoietic cell proliferation in the spleen were significantly increased in all dosed groups of mice (Table 9, Table A-3, and Table A-4). With the exceptions of 6.25% males and 25% females, the incidences of lymphoid hyperplasia were significantly increased in the mandibular lymph node of all dosed groups. Lymphoid hyperplasia occurred in the axillary lymph nodes of all mice, except one male in the 100% groups; one female in the 50% group also had axillary lymph node hyperplasia. Occurrences of these lesions were considered secondary to the lesions observed in the skin at the site of application. Bone marrow myeloid cell hyperplasia was characterized by increased numbers of hematopoietic cells (primarily granulocytes) within the marrow cavity of dosed animals. Splenic hematopoietic cell proliferation was characterized by expansion of the red pulp by myeloid and erythroid precursors and varying numbers of megakaryocytes. Lymphoid hyperplasia in the lymph nodes was characterized by increased numbers of lymphocytes in the lymphoid follicles and follicular and paracortical zones.

In the thymus, the incidences of atrophy were significantly increased in 25% or greater males compared to those in the respective controls (Table 9 and Table A-3). Atrophy consisted of depletion of thymocytes in the cortex of the thymus.

In the kidney, the incidence of nephropathy was significantly increased in 100% males compared to that in the untreated controls (Table 9 and Table A-3). Nephropathy consisted of sparsely scattered, focal areas of renal tubules lined by increased numbers of epithelial cells that had basophilic cytoplasm compared to surrounding normal tubules that were lined by epithelial cells that had eosinophilic cytoplasm.

## Genetic Toxicology

Cedarwood oil (0.33 to 333 µg/plate) was not mutagenic in Salmonella typhimurium strains TA98, TA100, or TA102 when tested with or without 10% induced rat liver S9 metabolic activation enzymes (Table E-1). In vivo, no significant increases in micronucleated erythrocytes (normochromatic erythrocytes; NCEs) were observed in blood samples from male B6C3F1/N mice following 3 months of dermal exposure to cedarwood oil (6.25% to 50%) (Table E-2). In female B6C3F1/N mice treated with cedarwood oil for 3 months, small increases in the frequencies of micronucleated erythrocytes were seen at the two highest doses (25% and 50%), but the mean value for micronucleated erythrocytes in each of these two treatment groups was not significantly elevated over the mean value in the vehicle control group. Because the trend test was significant (P = 0.011), the results of the micronucleus assay in female mice were judged to be equivocal. No significant alterations in the percentage of micronucleated reticulocytes (polychromatic erythrocytes; PCEs) were seen in male or female mice, suggesting that cedarwood oil applied dermally did not induce bone marrow toxicity.