# Materials and Methods

## Procurement and Characterization

### Virginia Cedarwood Oil

Prior to selecting the test article, NTP investigated the composition of selected components in six lots that were procured as Virginia cedarwood oil from three suppliers. The chromatographic profiles of the six lots were similar to each other. The composition of α-cedrene, β-cedrene, thujopsene, cuparene, and cedrol in these lots ranged from 18% to 40%, 4% to 8%, 16% to 31%, 2% to 4%, and 19% to 26%, respectively. Due to the close similarities between the procured lots, the lot selected for testing was based upon the availability in bulk quantity.

For the current 3-month dermal studies, Virginia cedarwood oil was obtained from Texarome, Inc. (Leakey, TX), in one lot (T122303DP). Identity, purity, and stability analyses were conducted by the analytical chemistry laboratory at Midwest Research Institute (Kansas City, MO) and the study laboratory at Battelle Columbus Operations (Columbus, OH) (Appendix F). Reports on analyses performed in support of the cedarwood oil studies are on file at the National Institute of Environmental Health Sciences.

The chemical, a pale yellow oily liquid with a cedar odor, was identified as cedarwood oil using infrared (IR) and proton nuclear magnetic resonance (NMR) spectroscopy.

Physical properties for lot T122303DP were determined by the analytical chemistry laboratory; optical rotation was −26.1° and specific gravity was 0.9581 at 24.8°C, refractive index was 1.5053 at 19°C, and viscosity was 22.6 cP at 22.2°C. The determined values for optical rotation, specific gravity, and refractive index were consistent with the reported values for cedarwood oil.^37^

The purity of lot T122303DP was determined based on a chromatography profile of the major components obtained by using gas chromatography (GC) with flame ionization detection (FID). Five compounds (α-cedrene, β-cedrene, thujopsene, cuparene, and cedrol) were selected as marker compounds and quantitated using standards obtained from Sigma-Aldrich Corporation (St. Louis, MO); the percentages were 27.01% α-cedrene, 6.05% β-cedrene, 19.64% thujopsene, 0.96% cuparene, and 21.83% cedrol. The components of lot T122303DP were also determined using GC with mass spectrometry (MS) detection. Ten marker compounds having peak areas of at least 1% of the total peak area were identified in this analysis: α-cedrene, β-cedrene, thujopsene, β-chamigrene, α-alaskene, α-cuprenene, β-himachalene, cuparene, cedrol, and widdrol. Headspace analyses for volatiles were conducted on samples of this lot using GC/MS both before and after homogenization at 50°C, and 15 components were identified in the chromatographic profiles; limonene (or an isomer), iso-italicene (or an isomer), italicene (or an isomer), α-cedrene, cis-β-farnesene (or an isomer), β-selinene (or an isomer), β-cedrene, thujopsene, β-chamigrene (or an isomer), α-alaskene (or an isomer), α-cuprenene (or an isomer), β-himachalene (or an isomer), cuparene, cedrol, and widdrol. No significant differences were observed between samples analyzed before and after homogenization. Taken together, the results of these characterization assays indicated that the composition of lot T122303DP was consistent with that reported in the literature for cedarwood oil.^38,37,39^

Stability studies of the bulk chemical were performed for samples stored at −20°, 5°, 25°, or 60°C in sealed amber glass vials; additional freeze/thaw analyses were also performed every 2 to 3 days during the 2-week stability studies. Stability was confirmed for at least 2 weeks for samples stored at temperatures up to 25°C in sealed amber glass vials. Freeze/thaw analyses indicated no decomposition due to repeated freezing and thawing.

To ensure stability, the bulk chemical was stored at approximately 25°C in the original sealed amber glass shipping bottles. Periodic reanalyses of the bulk chemical were performed during the 3-month studies using GC/FID and no degradation of the bulk chemical was detected.

### Ethanol

USP grade 95% ethanol was obtained from Spectrum Chemicals & Laboratory Products (Gardena, CA) in one lot (TP0179) and from AAPER Alcohol (Shelbyville, KY) in one lot (02K2JWB). Lot TP0179 was used in the 3-month dermal studies, and lot 02K2JWB was used in the dose formulation stability studies.

## Preparation and Analysis of Dose Formulations

The dose formulations were prepared four times by mixing cedarwood oil and 95% ethanol to give the required concentrations (Table F-2). The dose formulations were stored at approximately 25°C in amber glass bottles sealed with Teflon^®^-lined lids for up to 34 days.

Homogeneity and stability studies of a 9.5 mg/mL (0.95%) formulation in 95% ethanol were performed by the analytical chemistry laboratory using GC/FID. Based on these studies, homogeneity was confirmed and stability was confirmed for cedarwood oil formulations stored in amber glass containers sealed with Teflon^®^-lined lids for 1 day with expected losses of 6.2% or less for all components or stored for 42 days with expected losses of 10.4% or less. Cedarwood oil formulations were stable for up to 3 hours under simulated animal room conditions.

Periodic analyses of the dose formulations of cedarwood oil were conducted by the study laboratory using GC/FID. During the 3-month studies, the dose formulations were analyzed three times; all 15 dose formulations analyzed for rats and all 14 dose formulations for mice were within 10% of the target concentrations (Table F-3). Animal room samples of these dose formulations were also analyzed; all 15 for rats and all 14 for mice were within 10% of the target concentrations.

## Animal Source

Male and female F344/N rats and B6C3F1/N mice were obtained from the NTP colony at Taconic Farms, Inc. (Germantown, NY).

## Animal Welfare

Animal care and use are in accordance with the Public Health Service Policy on Humane Care and Use of Animals. All animal studies were conducted in an animal facility accredited by the Association for the Assessment and Accreditation of Laboratory Animal Care International. Studies were approved by the Battelle Columbus Operations Animal Care and Use Committee and conducted in accordance with all relevant NIH and NTP animal care and use policies and applicable federal, state, and local regulations and guidelines.

## Three-month Studies

On receipt, the rats and mice were 4 to 5 weeks old. Animals were quarantined for 13 or 14 days (rats) or 11 or 12 days (mice); rats were 6 to 7 weeks old and mice were 5 to 6 weeks old on the first day of dosing at the start of the studies. Before the studies began, five male and five female rats and mice were randomly selected for parasite evaluation and gross observation for evidence of disease. The health of the animals was monitored during the studies according to the protocols of the NTP Sentinel Animal Program (Appendix H). All test results were negative.

Groups of 10 male and 10 female rats and mice received no treatment (untreated control) or were administered cedarwood oil in 95% aqueous ethanol dermally at concentrations of 0% (vehicle control), 6.25%, 12.5%, 25%, 50%, or 100% (neat) 5 days per week for 14 weeks. Formulations were administered at a volume of 0.5 mL/kg body weight (rats) or 2.0 mL/kg (mice). These corresponded to applied doses of 31.25 to 500 mg cedarwood oil/kg body weight in rats and 125 to 2,000 mg/kg in mice. Doses were applied using a repeating pipette with a disposable tip to a consistent area that was shaved weekly. The shaved area was on the dorsal surface just posterior to the scapulae to the base of the tail and larger than the application site. Feed and water were available ad libitum. Rats and mice were housed individually. All animals were weighed and clinical observations were recorded initially, weekly, and at the end of the studies. Details of the study design and animal maintenance are summarized in Table 1. The feed was acceptable for use and information on feed composition and contaminants is provided in Appendix G.

Table 1 Experimental Design and Materials and Methods in the Three-month Dermal Studies of Cedarwood Oil

Three-month Study
Study Laboratory
Battelle Columbus Operations (Columbus, OH)
Strain and Species
F344/N rats B6C3F1/N mice
Animal Source
Taconic Farms, Inc. (Germantown, NY)
Time Held Before Studies
Rats: 13 (males) or 14 (females) days Mice: 11 (females) or 12 (males) days
Average Age When Studies Began
Rats: 6 to 7 weeks Mice: 5 to 6 weeks
Date of First Dose
Rats: June 15 (males) or 16 (females), 2005 Mice: June 13 (females) or 14 (males), 2005
Duration of Dosing
5 days per week for 14 weeks
Date of Last Dose
Rats: September 14 (males) or 15 (females), 2005 Mice: September 12 (females) or 13 (males), 2005
Necropsy Dates
Rats: September 15 (males) or 16 (females), 2005 Mice: September 13 (females) or 14 (males), 2005
Average Age at Necropsy
19 to 20 weeks
Size of Study Groups
10 males and 10 females
Method of Distribution
Animals were distributed randomly into groups of approximately equal initial mean body weights.
Animals per Cage
1
Method of Animal Identification
Tail tattoo
Diet
Irradiated NTP-2000 open formula wafer feed (Zeigler Brothers, Inc., Gardners, PA), available ad libitum, changed at least weekly
Water
Tap water (City of Columbus municipal supply) via automatic watering system (Edstrom Industries, Inc., Waterford, WI), available ad libitum
Cages
Polycarbonate [Allentown Caging Equipment Company, Allentown, NJ (rats), or Lab Products, Inc., Seaford, DE (mice)], changed weekly
Bedding
Heat-treated, irradiated hardwood Sani-Chips^®^ (P.J. Murphy Forest Products Corp., Montville, NJ), changed weekly
Rack Filters
Spun-bonded polyester (Snow Filtration Company, Cincinnati, OH), changed every 2 weeks
Racks
Stainless steel (Lab Products, Inc., Seaford, DE), changed every 2 weeks
Animal Room Environment
Temperature: 72° ± 3°F Relative humidity: 50% ± 15% Room fluorescent light: 12 hours/day Room air changes: 10/hour
Concentrations
Untreated control, 0% (vehicle control), 6.25%, 12.5%, 25%, 50%, or 100% (neat)
Type and Frequency of Observation
Observed twice daily; animals were weighed and clinical observations were recorded initially, weekly thereafter, and at the end of the studies.
Method of Euthanasia
Carbon dioxide asphyxiation
Necropsy
Necropsies were performed on all animals. Organs weighed were heart, right kidney, liver, lung, right testis, and thymus.
Clinical Pathology
Blood was collected from the retroorbital plexus of rats and the retroorbital sinus of mice at the end of the studies for hematology. Hematology: hematocrit; hemoglobin; erythrocyte, reticulocyte, and platelet counts; mean cell volume; mean cell hemoglobin; mean cell hemoglobin concentration; and leukocyte count and differentials
Histopathology
Complete histopathology was performed on rats in the untreated control, vehicle control, and 100% groups and mice in the untreated control, vehicle control, 50%, and 100% groups. In addition to gross lesions and tissue masses, the following tissues were examined: adrenal gland, bone with marrow, brain, clitoral gland, esophagus, eye, gallbladder (mice), Harderian gland, heart and aorta, large intestine (cecum, colon, rectum), small intestine (duodenum, jejunum, ileum), kidney, liver, lung (with mainstem bronchus), lymph nodes (mandibular and mesenteric), mammary gland, nose, ovary, pancreas, parathyroid gland, pituitary gland, preputial gland, prostate gland, salivary gland, seminal vesicle, skin (site of application), spleen, stomach (forestomach and glandular), testis (with epididymis), thymus, thyroid gland, trachea, urinary bladder, and uterus. The adrenal cortex (males), bone marrow, kidney (males), liver, skin at the site of application, and thyroid gland of rats and the bone marrow, kidney (males), liver, lymph nodes, skin at the site of application, spleen, and thymus of mice were examined in the remaining dosed groups.
Sperm Motility and Vaginal Cytology
At the end of the studies, sperm samples were collected from male rats in the vehicle control, 12.5%, 25%, and 50% groups and male mice in the vehicle control, 6.25%, 12.5%, and 25% groups for sperm motility evaluations. The following parameters were evaluated: spermatid heads per testis and per gram testis, and epididymal spermatozoal motility and concentration. The left cauda, left epididymis, and left testis were weighed. Vaginal samples were collected for up to 12 consecutive days prior to the end of the studies from female rats in the vehicle control, 12.5%, 25%, and 50% groups and female mice in the vehicle control, 6.25%, 12.5%, and 25% groups for vaginal cytology evaluations.

Animals were anesthetized with a carbon dioxide/oxygen mixture, and blood was collected from the retroorbital plexus of rats and the retroorbital sinus of mice at the end of the 3-month studies for hematology analyses. Blood samples were collected in tubes containing EDTA as the anticoagulant. Parameters were measured using an ADVIA^®^ 120 Hematology Analyzer (Bayer, Inc., Tarrytown, NY) using reagents supplied by the manufacturer. The parameters measured are listed in Table 1.

At the end of the 3-month studies, samples were collected for sperm motility or vaginal cytology evaluations on male and female rats in the vehicle control, 12.5%, 25%, and 50% groups, and male and female mice in the vehicle control, 6.25%, 12.5%, and 25% groups. The parameters evaluated are listed in Table 1. For 12 consecutive days prior to scheduled terminal euthanasia, the vaginal vaults of the females were moistened with saline, if necessary, and samples of vaginal fluid and cells were stained. Relative numbers of leukocytes, nucleated epithelial cells, and large squamous epithelial cells were determined and used to ascertain estrous cycle stage (i.e., diestrus, proestrus, estrus, and metestrus). Male animals were evaluated for sperm count and motility. The left testis and left epididymis were isolated and weighed. The tail of the epididymis (cauda epididymis) was then removed from the epididymal body (corpus epididymis) and weighed. Test yolk (rats) or modified Tyrone’s buffer (mice) was applied to slides and a small incision was made at the distal border of the cauda epididymis. The sperm effluxing from the incision were dispersed in the buffer on the slides, and the numbers of motile and nonmotile spermatozoa were counted for five fields per slide by two observers. Following completion of sperm motility estimates, each left cauda epididymis was placed in buffered saline solution. Caudae were finely minced, and the tissue was incubated in the saline solution and then heat fixed at 65°C. Sperm density was then determined microscopically with the aid of a hemacytometer. To quantify spermatogenesis, the testicular spermatid head count was determined by removing the tunica albuginea and homogenizing the left testis in phosphate-buffered saline containing 10% dimethyl sulfoxide. Homogenization-resistant spermatid nuclei were counted with a hemacytometer.

Necropsies were performed on all rats and mice. The heart, right kidney, liver, lung, right testis, and thymus were weighed. Tissues for microscopic examination were fixed and preserved in 10% neutral buffered formalin (eyes were first fixed in Davidson’s solution), processed and trimmed, embedded in paraffin, sectioned to a thickness of 4 to 6 µm, and stained with hematoxylin and eosin. Additional sections of the kidney from male rats were stained with the Mallory-Heidenhain stain for protein. Complete histopathologic examinations were performed by the study laboratory pathologist on rats in the untreated control, vehicle control, and 100% groups and mice in the untreated control, vehicle control, 50%, and 100% groups; the adrenal cortex (males), bone marrow, kidney (males only), liver, skin at the site of application, and thyroid gland of rats and the bone marrow, kidney (males only), liver, lymph nodes, skin at the site of application, spleen, and thymus of mice were examined in all remaining dosed groups. Table 1 lists the tissues and organs routinely examined.

After a review of the laboratory reports and selected histopathology slides by a quality assessment (QA) pathologist, the findings and reviewed slides were submitted to a NTP Pathology Working Group (PWG) coordinator for a second independent review. Any inconsistencies in the diagnoses made by the study laboratory and QA pathologists were resolved by the NTP pathology peer review process. Final diagnoses for reviewed lesions represent a consensus of the PWG or a consensus between the study laboratory pathologist, NTP pathologist, QA pathologist(s) and the PWG coordinator. Details of these review procedures have been described, in part, by Maronpot and Boorman^40^ and Boorman et al.^41^

## Statistical Methods

Responses at concentrations up to 50% were compared to those of the vehicle control group; responses at 100% were compared to those of the untreated control group. In addition, vehicle control groups were compared to untreated control groups for selected rat data.

### Calculation and Analysis of Lesion Incidences

The incidences of lesions are presented in Appendix A as the numbers of animals bearing such lesions at a specific anatomic site and the numbers of animals with that site examined microscopically. The Fisher exact test,^42^ a procedure based on the overall proportion of affected animals, was used to determine significance between dosed and untreated control or vehicle control animals.

## Analysis of Continuous Variables

For dosed groups compared to the vehicle control groups, two approaches were employed to assess the significance of pairwise comparisons in the analysis of continuous variables. Organ and body weight data, which historically have approximately normal distributions, were analyzed with the parametric multiple comparison procedures of Dunnett^43^ and Williams.^44,45^ Hematology, spermatid, and epididymal spermatozoal data, which have typically skewed distributions, were analyzed using the nonparametric multiple comparison methods of Shirley^46^ (as modified by Williams^47^) and Dunn.^48^ Jonckheere’s test^49^ was used to assess the significance of the dose-related trends and to determine whether a trend-sensitive test (Williams’ or Shirley’s test) was more appropriate for pairwise comparisons than a test that does not assume a monotonic dose-related trend (Dunnett’s or Dunn’s test). Prior to statistical analysis, extreme values identified by the outlier test of Dixon and Massey^50^ were examined by NTP personnel, and implausible values were eliminated from the analysis. Proportions of regular cycling females in each dosed group were compared to the vehicle control group using the Fisher exact test.^42^ Tests for extended periods of estrus, diestrus, metestrus, and proestrus, as well as skipped estrus and skipped diestrus, were constructed based on a Markov chain model proposed by Girard and Sager.^51^ For each dose group, a transition probability matrix was estimated for transitions among the proestrus, estrus, metestrus, and diestrus stages, with provision for extended stays within each stage as well as for skipping estrus or diestrus within a cycle. Equality of transition matrices among dose groups and between the vehicle control group and each dosed group was tested using chi-square statistics.

For comparison of the 100% (neat) groups to the untreated control groups, a t-test was used to determine significant differences in organ and body weight data for rats, and a Wilcoxon’s rank sum test was used for hematology data for rats.^52^

## Quality Assurance Methods

The 3-month studies were conducted in compliance with Food and Drug Administration Good Laboratory Practice Regulations.^53^ In addition, as records from the 3-month studies were submitted to the NTP Archives, these studies were audited retrospectively by an independent QA contractor. Separate audits covered completeness and accuracy of the pathology data, pathology specimens, final pathology tables, and a draft of this NTP Toxicity Study Report. Audit procedures and findings are presented in the reports and are on file at NIEHS. The audit findings were reviewed and assessed by NTP staff, and all comments were resolved or otherwise addressed during the preparation of this Toxicity Study Report.

## Genetic Toxicology

### Salmonella typhimurium Mutagenicity Test Protocol

Testing procedures used for cedarwood oil followed protocols reported by Zeiger et al.^54^ Cedarwood oil was sent to the laboratory as a coded sample. It was incubated with the Salmonella typhimurium tester strains TA98, TA100, and TA102 either in buffer or S9 mix (metabolic activation enzymes and cofactors from Aroclor 1254-induced male Sprague-Dawley rats) for 20 minutes at 37°C. Top agar supplemented with L-histidine and D-biotin was added, and the contents of the tubes were mixed and poured onto the surfaces of minimal glucose agar plates. Histidine-independent mutant colonies arising on these plates were counted following incubation for 2 days at 37°C.

Each trial consisted of triplicate plates of concurrent positive and negative controls and of at least five doses of cedarwood oil. The high dose was limited by toxicity to 33 µg/plate without S9 mix and 333 µg/plate with S9.

In this assay, a positive response is defined as a reproducible, dose-related increase in histidine-independent (revertant) colonies in any one strain/activation combination. An equivocal response is defined as an increase in revertants that is not dose related, is not reproducible, or is not of sufficient magnitude to support a determination of mutagenicity. A negative response is obtained when no increase in revertant colonies is observed following chemical treatment. There is no minimum percentage or fold increase required for a chemical to be judged positive or weakly positive, although positive calls are typically reserved for increases in mutant colonies that are at least twofold over background.

### Mouse Peripheral Blood Micronucleus Test Protocol

A detailed discussion of this assay is presented by MacGregor et al.^55^ At the termination of the 3-month study, peripheral blood samples were obtained from male and female mice. Smears were immediately prepared and fixed in absolute methanol. The methanol-fixed slides were stained with acridine orange and coded. Slides were scanned to determine the frequency of micronucleated cells in 2,000 normochromatic erythrocytes (NCEs) in each of five animals per dose group. In addition, the percentage of polychromatic erythrocytes (PCEs) in a population of 1,000 erythrocytes was determined as a measure of bone marrow toxicity.

The results were tabulated as the mean of the pooled results from all animals within a treatment group, plus or minus the standard error of the mean. The frequency of micronucleated cells among NCEs was analyzed by a statistical software package that tested for increasing trend over dose groups using a one-tailed Cochran-Armitage trend test, followed by pairwise comparisons between each dosed group and the vehicle control group. In the presence of excess binomial variation, as detected by a binomial dispersion test, the binomial variance of the Cochran-Armitage test was adjusted upward in proportion to the excess variation. In the micronucleus test, an individual trial is considered positive if the trend test P value is less than or equal to 0.025 and the P value for any single dosed group is less than or equal to 0.025 divided by the number of dosed groups. Trials with either a significant trend or a significant dose are judged to be equivocal. The absence of a trend and a significant dose results in a negative call. Ultimately, the scientific staff determines the final call after considering the results of statistical analyses, reproducibility of any effects observed, and the magnitudes of those effects.

### Evaluation Protocol

These are the basic guidelines for arriving at an overall assay result for assays performed by the National Toxicology Program. Statistical as well as biological factors are considered. For an individual assay, the statistical procedures for data analysis have been described in the preceding protocols. There have been instances, however, in which multiple samples of a chemical were tested in the same assay, and different results were obtained among these samples and/or among laboratories. Results from more than one aliquot or from more than one laboratory are not simply combined into an overall result. Rather, all the data are critically evaluated, particularly with regard to pertinent protocol variations, in determining the weight-of-evidence for an overall conclusion of chemical activity in an assay. In addition to multiple aliquots, the in vitro assays have another variable that must be considered in arriving at an overall test result. In vitro assays are conducted with and without exogenous metabolic activation. Results obtained in the absence of activation are not combined with results obtained in the presence of activation; each testing condition is evaluated separately. The results presented in the Abstract of this Toxicity Report represent a scientific judgment of the overall evidence for activity of the chemical in an assay.