# Appendix H Sentinel Animal Program

## H.1 Methods

Rodents used in the National Toxicology Program are produced in optimally clean facilities to eliminate potential pathogens that may affect study results. The Sentinel Animal Program is part of the periodic monitoring of animal health that occurs during the toxicologic evaluation of test compounds. Under this program, the disease state of the rodents is monitored via sera or feces from extra (sentinel) or dosed animals in the study rooms. The sentinel animals and the study animals are subject to identical environmental conditions. Furthermore, the sentinel animals come from the same production source and weanling groups as the animals used for the studies of test compounds.

Blood samples were collected, allowed to clot, and the serum was separated. The serum samples were processed appropriately, sent to BioReliance Corporation (Rockville, MD), and evaluated for the presence of pathogens. The laboratory methods and agents for which testing was performed are tabulated below; the times at which samples were collected during the studies are also listed.

Table H-1 Laboratory Methods and Agents Tested for in the Sentinel Animal Program

Method and Test | Time of Collection
Rats
ELISA
PVM (pneumonia virus of mice) | Study start, 4 weeks, study termination
RCV/SDA (rat coronavirus/sialodacryoadenitis virus) | Study start, 4 weeks, study termination
Sendai | Study start, 4 weeks, study termination
Immunofluorescence Assay
Parvovirus | Study start, 4 weeks, study termination
Mice
ELISA
Ectromelia virus | Study start, 4 weeks, study termination
EDIM (epizootic diarrhea of infant mice) | Study start, 4 weeks, study termination
GDVII (mouse encephalomyelitis virus) | Study start, 4 weeks, study termination
LCM (lymphocytic choriomeningitis virus) | Study start, 4 weeks, study termination
Mouse adenoma virus-1 | Study start, 4 weeks, study termination
MHV (mouse hepatitis virus) | Study start, 4 weeks, study termination
MMV VP2 (mouse minute virus) | Study start, 4 weeks, study termination
MPV VP2 (mouse parvovirus) | Study start, 4 weeks, study termination
PVM | Study start, 4 weeks, study termination
Reovirus | Study start, 4 weeks, study termination
Sendai | Study start, 4 weeks, study termination

## H.2 Results

All test results were negative.