# Appendix F Chemical Characterization and Dose Formulation Studies

## F.1 Procurement and Characterization

### F.1.1 Cedarwood Oil

Prior to selecting the test article, NTP investigated the composition of selected components in six lots that were procured as Virginia cedarwood oil from three suppliers. The chromatographic profiles of the six lots were similar to each other. The composition of α-cedrene, β-cedrene, thujopsene, cuparene, and cedrol in these lots ranged from 18% to 40%, 4% to 8%, 16% to 31%, 2% to 4%, and 19% to 26%, respectively. Due to the close similarities between the procured lots, the lot selected for testing was based upon the availability in bulk quantity.

For the current 3-month dermal studies, cedarwood oil was obtained from Texarome, Inc. (Leakey, TX), in one lot (T122303DP). Identity, purity, and stability analyses were conducted by the analytical chemistry laboratory at Midwest Research Institute (Kansas City, MO) and the study laboratory at Battelle Columbus Operations (Columbus, OH). Reports on analyses performed in support of the cedarwood oil studies are on file at the National Institute of Environmental Health Sciences.

The chemical, a pale yellow oily liquid with a cedar odor, was identified as cedarwood oil by the analytical chemistry laboratory using infrared (IR) and proton nuclear magnetic resonance (NMR) spectroscopy and by the study laboratory using IR spectroscopy. All IR spectra were consistent with the literature spectra for cedarwood oil^67^; NMR spectra were consistent with spectra previously obtained from another lot of cedarwood oil. Representative IR and NMR spectra are presented in Figure F-1 and Figure F-2, respectively.

Physical properties for lot T122303DP were determined by the analytical chemistry laboratory; optical rotation was −26.1°, specific gravity was 0.9581 at 24.8°C, refractive index was 1.5053 at 19°C, and viscosity was 22.6 cP at 22.2°C. The determined values for optical rotation, specific gravity, and refractive index were consistent with the reported values for cedarwood oil.^37^

The purity of lot T122303DP was determined by the analytical chemistry laboratory based on a chromatography profile of the major components obtained by using gas chromatography (GC) with flame ionization detection (FID) by system A (Table F-1). Five compounds (α-cedrene, β-cedrene, thujopsene, cuparene, and cedrol) were selected as marker compounds and quantitated using standards obtained from Sigma-Aldrich Corporation (St. Louis, MO). Weight percent concentrations of the five selected marker compounds were determined to be α-cedrene, 27.01%, β-cedrene, 6.05%, thujopsene, 19.64%, cuparene, 0.96%, and cedrol, 21.83%; these results were not significantly changed by homogenization of the bulk chemical (heating to 50°C) prior to analysis.

The analytical chemistry laboratory also determined the components of lot T122303DP using GC with mass spectrometry (MS) detection by system B to profile the major components of the test article. Ten marker compounds having peak areas of at least 1% of the total peak area were identified in this analysis; α-cedrene, β-cedrene, thujopsene, β-chamigrene, α-alaskene, α-cuprenene, β-himachalene, cuparene, cedrol, and widdrol. Headspace analysis for volatiles were conducted on samples of this lot using GC/MS by system B both before and after homogenization at 50°C, and 15 components were identified in the chromatographic profiles: limonene (or an isomer), iso-italicene (or an isomer), italicene (or an isomer), α-cedrene, cis-β-farnesene (or an isomer), β-selinene (or an isomer), β-cedrene, thujopsene, β-chamigrene (or an isomer), α-alaskene (or an isomer), α-cuprenene (or an isomer), β-himachalene (or an isomer), cuparene, cedrol, and widdrol. No significant differences were observed between samples analyzed before and after homogenization. Taken together, the results of these characterization assays indicated that the composition of lot T122303DP was consistent with that reported in the literature for cedarwood oil.^38,37,39^

One aliquot of cedarwood oil was submitted to Covance Laboratories, Inc. (Madison, WI) for nutritional and contaminant testing using standard methods. For this lot, mercury and molybdenum were detected at 13.2 ppb and 18.2 ppb, respectively. The other metals (antimony, arsenic, cadmium, and lead) were below the limit of quantitation of the assay (<10 ppb). For mycotoxin analyses, levels of aflatoxins B1, B2, G1, and G2 were all less than 0.500 ppb; levels of ochratoxin and zearalinine were less than 1 and 20 ppb, respectively. The pesticide screen experienced significant matrix effects that prevented quantitation of analytes.

Stability studies of the bulk chemical were performed by the analytical chemistry laboratory. GC/FID was performed using system A for samples stored at −20°, 5°, 25°, or 60°C in sealed amber glass vials; additional freeze/thaw analyses were also performed every 2 to 3 days during the 2-week stability studies. Stability was confirmed for at least 2 weeks for samples stored at temperatures up to 25°C in sealed amber glass vials. Freeze/thaw analyses indicated no decomposition due to repeated freezing and thawing.

To ensure stability, the bulk chemical was stored at approximately 25°C in the original sealed amber glass shipping bottles. Periodic reanalyses of the bulk chemical were performed by the study laboratory during the 3-month studies using GC/FID by system A; no degradation of the bulk chemical was detected.

### F.1.2 Ethanol

USP grade 95% ethanol was obtained from Spectrum Chemicals & Laboratory Products (Gardena, CA) in one lot (TP0179) and from AAPER Alcohol (Shelbyville, KY) in one lot (02K2JWB). Lot TP0179 was used in the 3-month dermal studies, and lot 02K2JWB was used in the dose formulation stability studies.

Lot TP0179, a clear liquid, was identified as ethanol by the study laboratory using IR spectroscopy; the IR spectrum was consistent with a literature spectrum^68^ of ethanol. The purity of lot TP0179 was determined by the study laboratory using GC/FID by system C; no impurities greater than 0.1% of the total peak area were detected. No benzene was detected in the test article using GC/FID by system D.

## F.2 Preparation and Analysis of Dose Formulations

The dose formulations were prepared four times by mixing cedarwood oil and 95% ethanol to give the required concentrations (Table F-2). The dose formulations were stored at approximately 25°C in amber glass bottles sealed with Teflon^®^-lined lids for up to 34 days.

Stability studies of a 9.5 mg/mL (0.95%) formulation in 95% ethanol were performed by the analytical chemistry laboratory using GC/FID by system E (Table F-1). Based on these studies, it was determined that cedarwood oil formulations could be stored in amber glass containers sealed with Teflon^®^-lined lids for 1 day with expected losses of 6.2% or less for all components or stored for 42 days with expected losses of 10.4% or less. Cedarwood oil formulations were stable for up to 3 hours under simulated animal room conditions.

Periodic analyses of the dose formulations of cedarwood oil were conducted by the study laboratory using GC/FID by a system similar to system E. During the 3-month studies, the dose formulations were analyzed three times; all 15 dose formulations analyzed for rats and all 14 dose formulations for mice were within 10% of the target concentrations (Table F-3). Animal room samples of these dose formulations were also analyzed; all 15 for rats and all 14 for mice were within 10% of the target concentrations.

Table F-1 Gas Chromatography Systems Used in the Three-month Dermal Studies of Cedarwood Oil^a^

Detection System | Column | Carrier Gas | Oven Temperature Program
System A
Flame ionization | DB-WAX, 30 m × 0.53 mm, 1.0 µm film (J&W Scientific, Folsom, CA) | Helium at 10 mL/minute | 60°C for 2 minutes, then 3°C/minute to 220°C
System B
Mass spectrometry | DB-WAX, 30 m × 0.25 mm, 0.5 µm film (J&W Scientific) | Helium at 1 mL/minute | 60°C for 3 minutes, then 3°C/minute to 220°C
System C
Flame ionization | DB-WAX, 30 m × 0.53 mm, 1.0 µm film (J&W Scientific) | Helium at 10 mL/minute | 40°C for 5 minutes, then 10°C/minute to 220°C, held for 5 minutes
System D
Flame ionization | Rtx^®^-5, 30 m × 0.53 mm, 1.5 µm film (Restek, Bellefonte, PA) | Helium at 10 mL/minute | 40°C for 3 minutes, then 10°C/minute to 200°C, held for 3 minutes
System E
Flame ionization | DB-WAX, 30 m × 0.53 mm, 1.0 µm film (J&W Scientific) | Helium at 10 mL/minute | 60°C for 3 minutes, then 3°C/minute to 220°C, held for 2 minutes

^a^ The gas chromatographs were manufactured by Agilent Technologies, Inc. (Santa Clara, CA; systems A, C, D, and E) or Thermo Fisher Scientific, Inc., (Waltham, MA; system B). The mass spectrometer was manufactured by Fisons (Sanofi, Bridgewater, NJ).

Table F-2 Preparation and Storage of Dose Formulations in the Three-month Dermal Studies of Cedarwood Oil

Three-month Study
Preparation
For the 6.25%, 12.5%, 25%, and 50% formulations, the appropriate amount of cedarwood oil was measured in a graduated cylinder and transferred with at least three ethanol rinses into a calibrated mixing container that contained 95% ethanol, diluted to a final volume with 95% ethanol, shaken by hand for 2 minutes, inverted at least 10 times, and then stirred on a stirplate for approximately 5 minutes at a speed that produced a vigorous vortex. Undiluted cedarwood oil was dispensed directly into amber glass dose formulation bottles as the 100% (neat) formulation. The dose formulations were prepared four times during the studies.
Chemical Lot Number
T122303DP
Maximum Storage Time
34 days
Storage Conditions
Stored in amber glass bottles sealed with Teflon^®^-lined lids at approximately 25°C.
Study Laboratory
Battelle Columbus Operations (Columbus, OH)

Table F-3 Results of Analyses of Dose Formulations Administered to Rats and Mice in the Three-month Dermal Studies of Cedarwood Oil^a^

Date Prepared | Date Analyzed | Target Concentration (%) | Determined Concentration^b^ (%) | Difference from Target (%)
Rats
May 31, 2005 | June 3-4, 2005 | 6.25 | 6.244 | 0
| | 12.5 | 12.31 | −2
| | 25 | 25.20 | +1
| | 50 | 53.20 | +6
| | 100 | 101.8 | +2
| July 8-10, 2005^c^ | 6.25 | 6.291 | +1
| | 12.5 | 12.65 | +1
| | 25 | 25.75 | +3
| | 50 | 52.15 | +4
| July 11-12, 2005^c^ | 100 | 97.87 | −2
June 23, 2005 | June 24-25, 2005 | 6.25 | 6.071 | −3
| | 12.5 | 12.20 | −2
| | 25 | 24.69 | −1
| | 50 | 50.11 | 0
| | 100 | 99.63 | 0
| July 27-29, 2005^c^ | 6.25 | 6.213 | −1
| | 12.5 | 12.25 | −2
| | 25 | 25.01 | 0
| | 50 | 49.53 | −1
| | 100 | 97.89 | −2
August 16, 2005 | August 16-17, 2005 | 6.25 | 6.209 | −1
| | 12.5 | 11.97 | −4
| | 25 | 23.68 | −5
| | 50 | 49.21 | −2
| | 100 | 93.85 | −6
| September 19-22, 2005^c^ | 6.25 | 6.380 | +2
| | 12.5 | 12.79 | +2
| | 25 | 25.46 | +2
| | 50 | 52.34 | +5
| | 100 | 101.2 | +1
Mice
May 31, 2005 | June 3-4, 2005 | 6.25 | 6.244 | 0
| | 12.5 | 12.31 | −2
| | 25 | 25.20 | +1
| | 50 | 53.20 | +6
| | 100 | 101.8 | +2
| July 8-10, 2005^d^ | 6.25 | 6.256 | 0
| | 12.5 | 12.59 | +1
| | 25 | 25.64 | +3
| | 50 | 53.00 | +6
| July 11-12, 2005^d^ | 100 | 98.54 | −1
June 23, 2005 | June 24-25, 2005 | 6.25 | 6.071 | −3
| | 12.5 | 12.20 | −2
| | 25 | 24.69 | −1
| | 50 | 50.11 | 0
| | 100 | 99.63 | 0
| July 27-29, 2005^d^ | 6.25 | 5.929 | −5
| | 12.5 | 11.84 | −5
| | 25 | 23.87 | −5
| | 50 | 47.41 | −5
| | 100 | 93.06 | −7
August 16, 2005 | August 16-17, 2005 | 6.25 | 6.209 | −1
| | 12.5 | 11.97 | −4
| | 25 | 23.68 | −5
| | 50 | 49.21 | −2
| September 19-22, 2005^d^ | 6.25 | 6.377 | +2
| | 12.5 | 12.82 | +3
| | 25 | 25.45 | +2
| | 50 | 52.20 | +4

^a^ The vehicle control was also analyzed and was below the limit of quantitation.

^b^ Results of duplicate analyses.

^c^ Animal room samples for rats.

^d^ Animal room samples for mice.

Figure F-1

Infrared Absorption Spectrum of Cedarwood Oil

Figure F-2

Proton Nuclear Magnetic Resonance Spectrum of Cedarwood Oil