# Appendix E Genetic Toxicology

Table E-1 Mutagenicity of Cedarwood Oil in Salmonella typhimurium^a^

Strain | Dose (μg/plate) | Without S9 | With 10% Rat S9
TA102 | 0 | 315 ± 14 | 405 ± 6
| 0.33 | 278 ± 6
| 1.0 | 298 ± 3
| 3.3 | 282 ± 6 | 421 ± 3
| 10 | 311 ± 17 | 401 ± 10
| 33 | 240 ± 12 | 404 ± 9
| 100 | | 386 ± 16
| 333 | | 346 ± 2
Trial summary | | Negative | Negative
Positive control^b^ | | 976 ± 7 | 1,398 ± 55
TA100 | 0 | 160 ± 10 | 152 ± 14
| 0.33 | 145 ± 3
| 1.0 | 144 ± 6
| 3.3 | 141 ± 9 | 142 ± 2
| 10 | 126 ± 4 | 136 ± 8
| 33 | 31 ± 11^c^ | 145 ± 2
| 100 | | 124 ± 10
| 333 | | 85 ± 7^c^
Trial summary | | Negative | Negative
Positive control | | 630 ± 13 | 512 ± 86
TA98 | 0 | 21 ± 3 | 34 ± 1
| 0.33 | 17 ± 2
| 1.0 | 16 ± 2
| 3.3 | 26 ± 2 | 31 ± 3
| 10 | 22 ± 4^d^ | 27 ± 6
| 33 | 14 ± 2^c^ | 34 ± 3
| 100 | | 34 ± 4
| 333 | | 0 ± 0^c^
Trial summary | | Negative | Negative
Positive control | | 83 ± 4 | 676 ± 3

^a^ Study was performed at BioReliance Corporation. The detailed protocol is presented by Zeiger et al.^54^ Data are presented as revertants/plate (mean ± standard error) from three plates. 0 μg/plate was the solvent control.

^b^ The positive controls in the absence of metabolic activation were sodium azide (TA100), 4-nitro-o-phenylenediamine (TA98), and methyl methanesulfonate (TA102). The positive control for metabolic activation with all strains was 2-aminoanthracene.

^c^ Slight toxicity.

^d^ Contamination.

Table E-2 Frequency of Micronuclei in Peripheral Blood Erythrocytes of Mice Following Dermal Administration of Cedarwood Oil for Three Months^a^

| Concentration (%) | Number of Mice with Erythrocytes Scored | Micronucleated NCEs/ 1,000 NCEs^b^ | P Value^c^ | PCEs^b^(%)
Male
95% Ethanol^d^ | 0 | 5 | 2.00 ± 0.32 | | 3.48 ± 0.09
Cedarwood oil | 6.25 | 5 | 2.00 ± 0.52 | 0.5000 | 3.58 ± 0.14
| 12.5 | 5 | 2.70 ± 0.20 | 0.1533 | 3.46 ± 0.10
| 25 | 5 | 2.20 ± 0.30 | 0.3787 | 3.06 ± 0.15
| 50 | 5 | 2.20 ± 0.41 | 0.3787 | 2.98 ± 0.15
| | | P = 0.209^e^
Female
95% Ethanol | 0 | 5 | 1.60 ± 0.37 | | 3.34 ± 0.19
Cedarwood oil | 6.25 | 5 | 1.50 ± 0.27 | 0.5713 | 3.30 ± 0.11
| 12.5 | 5 | 1.30 ± 0.41 | 0.7114 | 3.50 ± 0.22
| 25 | 5 | 2.60 ± 0.37 | 0.0612 | 3.40 ± 0.16
| 50 | 5 | 2.40 ± 0.29 | 0.1027 | 3.12 ± 0.19
| | | P = 0.011

^a^ Study was performed at ILS, Inc. The detailed protocol is presented by MacGregor et al.^55^ No data are available for 100% mice due to mortality. NCE = normochromatic erythrocyte; PCE = polychromatic erythrocyte.

^b^ Mean ± standard error.

^c^ Pairwise comparison with the vehicle control group; dosed group values are significant at P ≤ 0.006.

^d^ Vehicle control.

^e^ Significance of micronucleated NCEs/1,000 NCEs tested by the one-tailed trend test; significant at P ≤ 0.025.