# Appendix D Reproductive Tissue Evaluations and Estrous Cycle Characterization

Table D-1 Summary of Reproductive Tissue Evaluations for Male Rats in the Three-month Dermal Study of Cedarwood Oil^a^

| Vehicle Control | 12.5% | 25% | 50%
n | 10 | 10 | 10 | 10
Weights (g)
Necropsy body wt | 329 ± 4 | 316 ± 6 | 308 ± 10 | 301 ± 8*
L. Cauda epididymis | 0.1545 ± 0.0019 | 0.1466 ± 0.0037 | 0.1495 ± 0.0072 | 0.1495 ± 0.0079
L. Epididymis | 0.4592 ± 0.0120 | 0.4424 ± 0.0115 | 0.4502 ± 0.0171 | 0.4416 ± 0.0138
L. Testis | 1.4565 ± 0.0142 | 1.4440 ± 0.0070 | 1.4260 ± 0.0251 | 1.4240 ± 0.0257
Spermatid measurements
Spermatid heads (10^6^/testis) | 179.50 ± 4.85 | 187.63 ± 8.09 | 186.13 ± 10.08 | 197.63 ± 6.46
Spermatid heads (10^6^/g testis) | 138.35 ± 4.10 | 146.15 ± 6.60 | 147.21 ± 7.31 | 156.29 ± 4.67
Epididymal spermatozoal measurements
Sperm motility (%) | 84.7 ± 0.6 | 84.7 ± 0.7 | 83.7 ± 0.6 | 84.2 ± 0.8
Sperm (10^6^/cauda epididymis) | 115.0 ± 7.2 | 116.4 ± 7.7 | 121.4 ± 8.4 | 107.2 ± 9.9
Sperm (10^6^/g cauda epididymis) | 748.5 ± 51.7 | 794.9 ± 49.6 | 811.5 ± 36.4 | 716.3 ± 55.4

* Significantly different (P ≤ 0.05) from the vehicle control group by Dunnett’s test.

^a^ Data are presented as mean ± standard error. Differences from the vehicle control group are not significant by Dunnett’s test (tissue weights) or Dunn’s test (spermatid and epididymal spermatozoal measurements).

Table D-2 Estrous Cycle Characterization for Female Rats in the Three-month Dermal Study of Cedarwood Oil^a^

| Vehicle Control | 12.5% | 25% | 50%
Number weighed at necropsy | 10 | 10 | 10 | 10
Necropsy body wt (g) | 197 ± 2 | 193 ± 4 | 182 ± 4** | 179 ± 3**
Proportion of regular cycling females^b^ | 10/10 | 10/10 | 10/10 | 10/10
Estrous cycle length (days) | 5.0 ± 0.0 | 5.0 ± 0.0 | 5.1 ± 0.1 | 5.0 ± 0.0
Estrous stages (% of cycle)
Diestrus | 60.8 | 62.5 | 62.5 | 55.0
Proestrus | 20.0 | 17.5 | 16.7 | 20.8
Estrus | 19.2 | 19.2 | 19.2 | 22.5
Metestrus | 0.0 | 0.0 | 0.0 | 0.0
Uncertain diagnosis | 0.0 | 0.8 | 1.7 | 1.7

** Significantly different (P ≤ 0.01) from the vehicle control group by Williams’ test.

^a^ Necropsy body weights and estrous cycle length data are presented as mean ± standard error. Differences from the vehicle control group were not significant by Dunn’s test (estrous cycle length). By multivariate analysis of variance, dosed females do not differ significantly from the vehicle control females in the relative length of time spent in the estrous stages. Tests for equality of transition probability matrices among all groups and between the vehicle control group and each dosed group indicated no significant differences in transition probabilities among the groups.

^b^ Number of females with a regular cycle/number of females cycling.

Table D-3 Results of Vaginal Cytology Study Using the Transition Matrix Approach for Female Rats in the Three-month Dermal Study of Cedarwood Oil

Stage | Comparison | P Value | Trend^a^
Overall tests | Overall | 0.989
Overall tests | 12.5% vs. vehicle controls | 0.953 | –
Overall tests | 25% vs. vehicle controls | 0.683 | –
Overall tests | 50% vs. vehicle controls | 0.975 | –
Extended estrus | Overall | 0.918
Extended estrus | 12.5% vs. vehicle controls | 0.604 | –
Extended estrus | 25% vs. vehicle controls | 1 | –
Extended estrus | 50% vs. vehicle controls | 0.604 | –
Extended diestrus | Overall | 0.993
Extended diestrus | 12.5% vs. vehicle controls | 1 | –
Extended diestrus | 25% vs. vehicle controls | 0.683 | –
Extended diestrus | 50% vs. vehicle controls | 0.996 | N
Extended metestrus | Overall | 1
Extended metestrus | 12.5% vs. vehicle controls | 1 | –
Extended metestrus | 25% vs. vehicle controls | 1 | –
Extended metestrus | 50% vs. vehicle controls | 1 | –
Extended proestrus | Overall | 1
Extended proestrus | 12.5% vs. vehicle controls | 1 | –
Extended proestrus | 25% vs. vehicle controls | 1 | –
Extended proestrus | 50% vs. vehicle controls | 1 | –
Skipped estrus | Overall | 1
Skipped estrus | 12.5% vs. vehicle controls | 1 | –
Skipped estrus | 25% vs. vehicle controls | 1 | –
Skipped estrus | 50% vs. vehicle controls | 1 | –
Skipped diestrus | Overall | 1
Skipped diestrus | 12.5% vs. vehicle controls | 1 | –
Skipped diestrus | 25% vs. vehicle controls | 1 | –
Skipped diestrus | 50% vs. vehicle controls | 1 | –

^a^ N means that the dosed group had a lower probability of transitioning to and/or from the relevant abnormal state (extended estrus, extended metestrus, extended proestrus, skipped estrus, or skipped diestrus) than did the vehicle control group.

Table D-4 Summary of Reproductive Tissue Evaluations for Male Mice in the Three-month Dermal Study of Cedarwood Oil^a^

| Vehicle Control | 6.25% | 12.5% | 25%
n | 10 | 10 | 9 | 10
Weights (g)
Necropsy body wt | 36.9 ± 0.8 | 36.0 ± 0.6 | 35.1 ± 1.1 | 33.1 ± 0.9**
L. Cauda epididymis | 0.0161 ± 0.0018 | 0.0143 ± 0.0009 | 0.0143 ± 0.0007 | 0.0141 ± 0.0005
L. Epididymis | 0.0436 ± 0.0023 | 0.0423 ± 0.0015 | 0.0396 ± 0.0012 | 0.0417 ± 0.0011
L. Testis | 0.1089 ± 0.0032 | 0.1100 ± 0.0022 | 0.1092 ± 0.0026 | 0.1094 ± 0.0025
Spermatid measurements
Spermatid heads (10^6^/testis) | 21.57 ± 0.72 | 21.42 ± 0.75 | 22.85 ± 0.60 | 21.98 ± 0.66^b^
Spermatid heads (10^6^/g testis) | 210.41 ± 9.00 | 208.10 ± 9.26 | 214.88 ± 5.46 | 217.22 ± 5.31^b^
Epididymal spermatozoal measurements
Sperm motility (%) | 83.1 ± 0.3 | 81.6 ± 1.9 | 82.7 ± 0.6 | 83.9 ± 0.4
Sperm (10^6^/cauda epididymis) | 12.5 ± 1.4 | 12.6 ± 1.1 | 12.6 ± 1.0 | 13.3 ± 2.1
Sperm (10^6^/g cauda epididymis) | 820.3 ± 105.9 | 884.7 ± 70.4 | 886.8 ± 69.1 | 1,022.9 ± 121.2

** Significantly different (P ≤ 0.01) from the vehicle control group by Williams’ test.

^a^ Data are presented as mean ± standard error. Differences from the vehicle control group are not significant by Dunnett’s test (tissue weights) or Dunn’s test (spermatid and epididymal spermatozoal measurements).

^b^ n = 9.

Table D-5 Estrous Cycle Characterization for Female Mice in the Three-month Dermal Study of Cedarwood Oil^a^

| Vehicle Control | 6.25% | 12.5% | 25%
Number weighed at necropsy | 10 | 10 | 10 | 10
Necropsy body wt (g) | 34.7 ± 1.1 | 34.0 ± 0.9 | 30.5 ± 0.7** | 28.1 ± 0.6**
Proportion of regular cycling females^b^ | 8/10 | 8/10 | 9/10 | 9/10
Estrous cycle length (days) | 4.2 ± 0.14 | 4.5 ± 0.4 | 3.9 ± 0.09 | 4.1 ± 0.15
Estrous stages (% of cycle)
Diestrus | 31.7 | 30.0 | 32.5 | 26.7
Proestrus | 0.0 | 0.0 | 0.0 | 0.0
Estrus | 45.0 | 45.8 | 45.8 | 45.0
Metestrus | 21.7 | 24.2 | 21.7 | 24.2
Uncertain diagnoses | 1.7 | 0.0 | 0.0 | 4.2

** Significantly different (P ≤ 0.01) from the vehicle control group by Williams’ test.

^a^ Necropsy body weights and estrous cycle length data are presented as mean ± standard error. Differences from the vehicle control group are not significant by Dunn's test (estrous cycle length). By multivariate analysis of variance, dosed females do not differ significantly from the vehicle control females in the relative length of time spent in the estrous stages. Tests for equality of transition probability matrices among all groups and between the vehicle control group and each dosed group indicated no significant differences in transition probabilities among the groups.

^b^ Number of females with a regular cycle/number of females cycling.

Table D-6 Results of Vaginal Cytology Study Using the Transition Matrix Approach for Female Mice in the Three-month Dermal Study of Cedarwood Oil

Stage | Comparison | P Value | Trend^a^
Overall tests | Overall | 0.641
Overall tests | 6.25% vs. vehicle controls | 0.828 | N
Overall tests | 12.5% vs. vehicle controls | 0.401 | N
Overall tests | 25% vs. vehicle controls | 0.358 | –
Extended estrus | Overall | 0.848
Extended estrus | 6.25% vs. vehicle controls | 0.758 | N
Extended estrus | 12.5% vs. vehicle controls | 0.347 | N
Extended estrus | 25% vs. vehicle controls | 0.994 | –
Extended diestrus | Overall | 0.985
Extended diestrus | 6.25% vs. vehicle controls | 0.882 | N
Extended diestrus | 12.5% vs. vehicle controls | 0.882 | N
Extended diestrus | 25% vs. vehicle controls | 0.777 | –
Extended metestrus | Overall | 1
Extended metestrus | 6.25% vs. vehicle controls | 1 | –
Extended metestrus | 12.5% vs. vehicle controls | 1 | –
Extended metestrus | 25% vs. vehicle controls | 1 | –
Extended proestrus | Overall | 1
Extended proestrus | 6.25% vs. vehicle controls | 1 | –
Extended proestrus | 12.5% vs. vehicle controls | 1 | –
Extended proestrus | 25% vs. vehicle controls | 1 | –
Skipped estrus | Overall | 1
Skipped estrus | 6.25% vs. vehicle controls | 1 | –
Skipped estrus | 12.5% vs. vehicle controls | 1 | –
Skipped estrus | 25% vs. vehicle controls | 1 | –
Skipped diestrus | Overall | 1
Skipped diestrus | 6.25% vs. vehicle controls | 1 | –
Skipped diestrus | 12.5% vs. vehicle controls | 1 | –
Skipped diestrus | 25% vs. vehicle controls | 1 | –

^a^ N means that the dosed group had a lower probability of transitioning to and/or from the relevant abnormal state (extended estrus, extended metestrus, extended proestrus, skipped estrus, or skipped diestrus) than did the vehicle control group.

Figure D-1

Vaginal Cytology Plots for Female Rats in the Three-month Dermal Study of Cedarwood Oil

D = diestrus, P = proestrus, E = estrus, IC = insufficient number of cells to determine stage.

Figure D-2

Vaginal Cytology Plots for Female Mice in the Three-month Dermal Study of Cedarwood Oil

D = diestrus, E = estrus, M = metestrus, IC = insufficient number of cells to determine stage.