# Appendix C Organ Weights and Organ-Weight-to-Body-Weight Ratios

Table C-1 Organ Weights and Organ-Weight-to-Body-Weight Ratios for Rats in the Three-month Dermal Study of Cedarwood Oil^a^

| Untreated Control | Vehicle Control | 6.25% | 12.5% | 25% | 50% | 100%
n | 10 | 10 | 10 | 10 | 10 | 10 | 8
Male
Necropsy body wt | 323 ± 4 | 329 ± 4 | 318 ± 5 | 316 ± 6 | 308 ± 10 | 301 ± 8* | 279 ± 7††
Heart
Absolute | 0.91 ± 0.01 | 0.91 ± 0.01 | 0.92 ± 0.02 | 0.91 ± 0.02 | 0.88 ± 0.03 | 0.90 ± 0.02 | 0.87 ± 0.02
Relative | 2.83 ± 0.02 | 2.77 ± 0.03 | 2.89 ± 0.05 | 2.90 ± 0.04 | 2.87 ± 0.03 | 2.99 ± 0.04** | 3.12 ± 0.05††
R. Kidney
Absolute | 1.09 ± 0.02 | 1.15 ± 0.02† | 1.08 ± 0.03 | 1.10 ± 0.02 | 1.12 ± 0.04 | 1.19 ± 0.03 | 1.33 ± 0.05††
Relative | 3.37 ± 0.05 | 3.51 ± 0.04† | 3.40 ± 0.04 | 3.50 ± 0.07 | 3.63 ± 0.06 | 3.96 ± 0.08** | 4.77 ± 0.11††
Liver
Absolute | 12.42 ± 0.37 | 12.75 ± 0.26 | 12.91 ± 0.38 | 12.47 ± 0.31 | 12.60 ± 0.49 | 13.07 ± 0.37 | 13.43 ± 0.42
Relative | 38.55 ± 1.21 | 38.79 ± 0.58 | 40.58 ± 0.97 | 39.52 ± 0.75 | 40.89 ± 0.86 | 43.49 ± 0.84** | 48.18 ± 1.31††
Lung
Absolute | 2.02 ± 0.11 | 1.98 ± 0.09 | 1.94 ± 0.11 | 1.93 ± 0.05 | 1.99 ± 0.11 | 0.95 ± 0.06 | 2.04 ± 0.10
Relative | 6.26 ± 0.32 | 6.02 ± 0.23 | 6.10 ± 0.30 | 6.12 ± 0.15 | 6.42 ± 0.20 | 6.51 ± 1.22 | 7.30 ± 0.31†
R. Testis
Absolute | 1.398 ± 0.018 | 1.384 ± 0.014 | 1.376 ± 0.024 | 1.314 ± 0.086 | 1.373 ± 0.025 | 1.389 ± 0.025 | 1.341 ± 0.020
Relative | 4.335 ± 0.058 | 4.216 ± 0.056 | 4.339 ± 0.107 | 4.144 ± 0.258 | 4.477 ± 0.094 | 4.627 ± 0.064* | 4.819 ± 0.106††
Thymus
Absolute | 0.282 ± 0.013 | 0.282 ± 0.006 | 0.277 ± 0.008 | 0.280 ± 0.010 | 0.245 ± 0.011* | 0.271 ± 0.014 | 0.223 ± 0.016†
Relative | 0.875 ± 0.044 | 0.857 ± 0.014 | 0.870 ± 0.023 | 0.887 ± 0.033 | 0.798 ± 0.032 | 0.904 ± 0.049 | 0.797 ± 0.051
Female
Necropsy body wt | 200 ± 4 | 197 ± 2 | 199 ± 4 | 194 ± 5 | 193 ± 4 | 182 ± 4* | 179 ± 3††
Heart
Absolute | 0.66 ± 0.02 | 0.64 ± 0.01 | 0.66 ± 0.02 | 0.65 ± 0.02 | 0.66 ± 0.02 | 0.63 ± 0.02 | 0.65 ± 0.02
Relative | 3.33 ± 0.08 | 3.27 ± 0.05 | 3.31 ± 0.05 | 3.35 ± 0.07 | 3.41 ± 0.05 | 3.46 ± 0.08 | 3.64 ± 0.09
R. Kidney
Absolute | 0.72 ± 0.01 | 0.71 ± 0.02 | 0.73 ± 0.02 | 0.71 ± 0.02 | 0.74 ± 0.02 | 0.70 ± 0.02 | 0.75 ± 0.01
Relative | 3.59 ± 0.07 | 3.59 ± 0.05 | 3.65 ± 0.04 | 3.63 ± 0.05 | 3.85 ± 0.06** | 3.86 ± 0.07** | 4.17 ± 0.09††
Liver
Absolute | 6.97 ± 0.18 | 7.02 ± 0.18 | 6.93 ± 0.23 | 7.10 ± 0.19 | 7.14 ± 0.18 | 6.80 ± 0.21 | 7.58 ± 0.13†
Relative | 34.94 ± 0.60 | 35.62 ± 0.79 | 34.74 ± 0.55 | 36.60 ± 0.62 | 36.98 ± 0.56 | 37.28 ± 0.56 | 42.30 ± 0.42††
Lung
Absolute | 1.68 ± 0.14 | 1.41 ± 0.07 | 1.56 ± 0.13 | 1.55 ± 0.08 | 1.53 ± 0.11 | 1.53 ± 0.12 | 1.45 ± 0.08
Relative | 8.44 ± 0.66 | 7.15 ± 0.33 | 7.82 ± 0.58 | 8.07 ± 0.50 | 7.89 ± 0.51 | 8.39 ± 0.63 | 8.06 ± 0.38
Thymus
Absolute | 0.279 ± 0.016 | 0.240 ± 0.006† | 0.263 ± 0.012 | 0.245 ± 0.013 | 0.244 ± 0.008 | 0.225 ± 0.009 | 0.213 ± 0.009††
Relative | 1.395 ± 0.071 | 1.220 ± 0.030† | 1.320 ± 0.055 | 1.265 ± 0.064 | 1.262 ± 0.036 | 1.236 ± 0.046 | 1.189 ± 0.055††

* Significantly different (P ≤ 0.05) from the vehicle control group by Williams’ or Dunnett’s test.

** P ≤ 0.01.

† Significantly different (P ≤ 0.05) from the untreated control group by t-test.

†† P ≤ 0.01.

^a^ Organ weights (absolute weights) and body weights are given in grams; organ-weight-to-body-weight ratios (relative weights) are given as mg organ weight/g body weight (mean ± standard error).

Table C-2 Organ Weights and Organ-Weight-to-Body-Weight Ratios for Mice in the Three-month Dermal Study of Cedarwood Oil^a^

| Vehicle Control | 6.25% | 12.5% | 25% | 50%
Male
n | 10 | 10 | 9 | 10 | 9
Necropsy body wt | 36.9 ± 0.8 | 36.0 ± 0.6 | 35.1 ± 1.1 | 33.1 ± 0.9** | 31.9 ± 0.7**
Heart
Absolute | 0.19 ± 0.01 | 0.22 ± 0.01 | 0.23 ± 0.01* | 0.23 ± 0.01** | 0.25 ± 0.02**
Relative | 5.15 ± 0.26 | 5.96 ± 0.21 | 6.60 ± 0.31** | 7.07 ± 0.33** | 7.80 ± 0.52**
R. Kidney
Absolute | 0.29 ± 0.01 | 0.29 ± 0.01 | 0.30 ± 0.01 | 0.28 ± 0.01 | 0.29 ± 0.01
Relative | 7.94 ± 0.12 | 8.16 ± 0.22 | 8.51 ± 0.21 | 8.35 ± 0.26 | 9.03 ± 0.14**
Liver
Absolute | 1.66 ± 0.04 | 1.76 ± 0.04 | 1.81 ± 0.05 | 1.77 ± 0.06 | 1.98 ± 0.04**
Relative | 45.06 ± 0.58 | 48.85 ± 1.18** | 51.51 ± 0.57** | 53.44 ± 1.06** | 62.12 ± 1.21**
Lung
Absolute | 0.31 ± 0.02 | 0.29 ± 0.01 | 0.29 ± 0.01 | 0.28 ± 0.01 | 0.28 ± 0.02
Relative | 8.39 ± 0.49 | 7.93 ± 0.37 | 8.31 ± 0.49 | 8.37 ± 0.24 | 8.67 ± 0.45
R. Testis
Absolute | 0.118 ± 0.003 | 0.117 ± 0.003 | 0.116 ± 0.004 | 0.118 ± 0.003 | 0.114 ± 0.004
Relative | 3.188 ± 0.054 | 3.258 ± 0.107 | 3.319 ± 0.094 | 3.568 ± 0.087** | 3.574 ± 0.107**
Thymus
Absolute | 0.048 ± 0.004 | 0.050 ± 0.002 | 0.044 ± 0.003 | 0.040 ± 0.001* | 0.038 ± 0.002*
Relative | 1.306 ± 0.077 | 1.374 ± 0.057 | 1.232 ± 0.063 | 1.224 ± 0.041 | 1.205 ± 0.073
Female
n | 10 | 10 | 10 | 10 | 9
Necropsy body wt | 34.7 ± 1.1 | 34.0 ± 0.9 | 30.5 ± 0.7** | 28.1 ± 0.6** | 30.2 ± 0.4**
Heart
Absolute | 0.18 ± 0.01 | 0.19 ± 0.01 | 0.20 ± 0.01* | 0.22 ± 0.01** | 0.24 ± 0.01**
Relative | 5.17 ± 0.17 | 5.54 ± 0.21 | 6.70 ± 0.37** | 7.70 ± 0.26** | 8.02 ± 0.31**
R. Kidney
Absolute | 0.19 ± 0.01 | 0.20 ± 0.00 | 0.20 ± 0.00 | 0.20 ± 0.00 | 0.24 ± 0.01**
Relative | 5.58 ± 0.18 | 5.94 ± 0.13 | 6.67 ± 0.18** | 7.07 ± 0.15** | 7.86 ± 0.16**
Liver
Absolute | 1.58 ± 0.05 | 1.65 ± 0.02 | 1.62 ± 0.03 | 1.60 ± 0.04 | 2.05 ± 0.05**
Relative | 45.61 ± 0.79 | 48.75 ± 0.79* | 53.24 ± 0.77** | 57.10 ± 1.02** | 67.80 ± 0.82**
Lung
Absolute | 0.30 ± 0.01 | 0.31 ± 0.01 | 0.29 ± 0.02 | 0.28 ± 0.01 | 0.27 ± 0.02
Relative | 8.78 ± 0.35 | 9.05 ± 0.27 | 9.40 ± 0.46 | 10.09 ± 0.37 | 9.06 ± 0.59
Thymus
Absolute | 0.061 ± 0.004 | 0.068 ± 0.004 | 0.051 ± 0.002* | 0.051 ± 0.003* | 0.045 ± 0.002**
Relative | 1.759 ± 0.087 | 1.990 ± 0.096 | 1.679 ± 0.063 | 1.802 ± 0.076 | 1.506 ± 0.070

* Significantly different (P ≤ 0.05) from the vehicle control group by Williams’ test.

** P ≤ 0.01.

^a^ Organ weights (absolute weights) and body weights are given in grams; organ-weight-to-body-weight ratios (relative weights) are given as mg organ weight/g body weight (mean ± standard error).