# Appendix B Hematology Results

Table B-1 Hematology Data for Rats in the Three-month Dermal Study of Cedarwood Oil^a^

| Untreated Control | Vehicle Control | 6.25% | 12.5% | 25% | 50% | 100%
Male
n | 10 | 9 | 10 | 9 | 10 | 10 | 8
Hematocrit (%) | 50.4 ± 0.6 | 49.2 ± 0.6 | 50.2 ± 0.4 | 48.8 ± 0.8 | 49.1 ± 0.6 | 48.5 ± 0.3 | 49.0 ± 0.6
Hemoglobin (g/dL) | 15.9 ± 0.2 | 15.6 ± 0.2 | 15.8 ± 0.1 | 15.4 ± 0.2 | 15.6 ± 0.2 | 15.4 ± 0.1 | 15.5 ± 0.1
Erythrocytes (10^6^/µL) | 9.31 ± 0.12 | 9.12 ± 0.11 | 9.25 ± 0.07 | 9.08 ± 0.14 | 9.14 ± 0.11 | 9.04 ± 0.05 | 9.03 ± 0.10†
Reticulocytes (10^3^/µL) | 223.8 ± 6.4 | 237.7 ± 8.0 | 229.5 ± 8.6 | 234.7 ± 10.3 | 202.1 ± 8.8* | 203.8 ± 8.6* | 188.4 ± 10.8†
Mean cell volume (fL) | 54.1 ± 0.2 | 54.0 ± 0.2 | 54.2 ± 0.2 | 53.8 ± 0.1 | 53.7 ± 0.2 | 53.7 ± 0.2 | 54.3 ± 0.1
Mean cell hemoglobin (pg) | 17.1 ± 0.1 | 17.1 ± 0.1 | 17.1 ± 0.1 | 17.0 ± 0.1 | 17.0 ± 0.1 | 17.0 ± 0.1 | 17.2 ± 0.1
Mean cell hemoglobin concentration (g/dL) | 31.5 ± 0.2 | 31.7 ± 0.1 | 31.5 ± 0.1 | 31.6 ± 0.1 | 31.7 ± 0.1 | 31.6 ± 0.1 | 31.6 ± 0.1
Platelets (10^3^/µL) | 545 ± 16 | 579 ± 13 | 577 ± 20 | 552 ± 50 | 559 ± 42 | 578 ± 18 | 632 ± 18††
Leukocytes (10^3^/µL) | 8.16 ± 0.36 | 8.98 ± 0.50 | 8.87 ± 0.38 | 9.35 ± 0.42 | 8.89 ± 0.23 | 9.62 ± 0.28 | 10.60 ± 0.17††
Segmented neutrophils (10^3^/µL) | 1.07 ± 0.05 | 1.23 ± 0.06 | 1.43 ± 0.09 | 1.33 ± 0.08 | 1.35 ± 0.10 | 1.70 ± 0.13* | 3.28 ± 0.21††
Lymphocytes (10^3^/µL) | 6.73 ± 0.32 | 7.41 ± 0.48 | 7.05 ± 0.33 | 7.62 ± 0.42 | 7.17 ± 0.25 | 7.54 ± 0.33 | 6.81 ± 0.26
Monocytes (10^3^/µL) | 0.22 ± 0.02 | 0.21 ± 0.02 | 0.25 ± 0.02 | 0.24 ± 0.03 | 0.22 ± 0.01 | 0.22 ± 0.01 | 0.35 ± 0.02††
Basophils (10^3^/µL) | 0.044 ± 0.005 | 0.068 ± 0.010 | 0.048 ± 0.004 | 0.064 ± 0.005 | 0.059 ± 0.003 | 0.060 ± 0.006 | 0.055 ± 0.006
Eosinophils (10^3^/µL) | 0.09 ± 0.01 | 0.06 ± 0.01 | 0.09 ± 0.01* | 0.08 ± 0.01 | 0.08 ± 0.01 | 0.10 ± 0.02 | 0.11 ± 0.01
Female
n | 10 | 8 | 9 | 9 | 10 | 7 | 9
Hematocrit (%) | 49.3 ± 1.4 | 47.5 ± 0.3 | 48.4 ± 0.9 | 47.8 ± 0.9 | 47.1 ± 0.5 | 48.9 ± 1.1 | 46.5 ± 0.6†
Hemoglobin (g/dL) | 16.1 ± 0.4 | 15.6 ± 0.1 | 15.8 ± 0.2 | 15.7 ± 0.2 | 15.6 ± 0.1 | 15.9 ± 0.3 | 15.2 ± 0.2†
Erythrocytes (10^6^/µL) | 8.72 ± 0.20 | 8.42 ± 0.07 | 8.50 ± 0.11 | 8.50 ± 0.12 | 8.37 ± 0.07 | 8.62 ± 0.16 | 8.34 ± 0.09
Reticulocytes (10^3^/µL) | 210.4 ± 7.7 | 202.4 ± 9.8 | 222.9 ± 15.2 | 200.9 ± 9.4 | 205.5 ± 7.2 | 187.1 ± 10.3 | 191.2 ± 4.5
Mean cell volume (fL) | 56.5 ± 0.4 | 56.5 ± 0.4 | 56.9 ± 0.3 | 56.2 ± 0.4 | 56.2 ± 0.3 | 56.7 ± 0.4 | 55.9 ± 0.2
Mean cell hemoglobin (pg) | 18.5 ± 0.1 | 18.5 ± 0.1 | 18.6 ± 0.1 | 18.4 ± 0.1 | 18.6 ± 0.1 | 18.4 ± 0.1 | 18.3 ± 0.1†
Mean cell hemoglobin concentration (g/dL) | 32.7 ± 0.2 | 32.8 ± 0.2 | 32.6 ± 0.2 | 32.8 ± 0.2 | 33.1 ± 0.2 | 32.6 ± 0.2 | 32.7 ± 0.2
Platelets (10^3^/µL) | 501 ± 47 | 608 ± 30 | 473 ± 57 | 464 ± 40* | 504 ± 38 | 588 ± 30 | 537 ± 56
Leukocytes (10^3^/µL) | 6.60 ± 0.37 | 6.85 ± 0.57 | 6.96 ± 0.19 | 7.04 ± 0.38 | 6.70 ± 0.40 | 8.89 ± 0.33** | 9.47 ± 0.35††
Segmented neutrophils (10^3^/µL) | 1.02 ± 0.11 | 1.15 ± 0.16 | 0.97 ± 0.07 | 1.22 ± 0.21 | 1.18 ± 0.08 | 1.50 ± 0.09* | 2.38 ± 0.15††
Lymphocytes (10^3^/µL) | 5.28 ± 0.31 | 5.39 ± 0.45 | 5.68 ± 0.21 | 5.49 ± 0.28 | 5.24 ± 0.35 | 6.97 ± 0.30* | 6.65 ± 0.29††
Monocytes (10^3^/µL) | 0.18 ± 0.01 | 0.20 ± 0.03 | 0.19 ± 0.01 | 0.19 ± 0.02 | 0.16 ± 0.02 | 0.25 ± 0.01 | 0.27 ± 0.03†
Basophils (10^3^/µL) | 0.046 ± 0.006 | 0.046 ± 0.006 | 0.038 ± 0.006 | 0.038 ± 0.007 | 0.037 ± 0.006 | 0.056 ± 0.008 | 0.056 ± 0.004
Eosinophils (10^3^/µL) | 0.07 ± 0.01 | 0.07 ± 0.01 | 0.08 ± 0.02 | 0.10 ± 0.02 | 0.09 ± 0.01 | 0.10 ± 0.02 | 0.12 ± 0.01†

* Significantly different (P ≤ 0.05) from the vehicle control group by Dunn’s or Shirley’s test.

** P ≤ 0.01.

† Significantly different (P ≤ 0.05) from the untreated control group by Wilcoxon’s rank sum test.

†† P ≤ 0.01.

^a^ Data are presented as mean ± standard error. Statistical tests were performed on unrounded data.

Table B-2 Hematology Data for Mice in the Three-month Dermal Study of Cedarwood Oil^a^

| Vehicle Control | 6.25% | 12.5% | 25% | 50%
Male
n | 9 | 10 | 9 | 10 | 9
Hematocrit (%) | 46.9 ± 0.8 | 45.4 ± 0.6 | 44.7 ± 0.6* | 44.0 ± 0.7** | 41.2 ± 0.7**
Hemoglobin (g/dL) | 15.9 ± 0.3 | 15.5 ± 0.2 | 15.1 ± 0.2* | 14.8 ± 0.2** | 13.9 ± 0.2**
Erythrocytes (10^6^/µL) | 10.30 ± 0.20 | 9.95 ± 0.13 | 9.77 ± 0.12* | 9.61 ± 0.12** | 9.06 ± 0.16**
Reticulocytes (10^3^/µL) | 328.3 ± 10.9 | 309.3 ± 11.4 | 321.2 ± 9.8 | 319.4 ± 9.6 | 330.7 ± 24.6
Mean cell volume (fL) | 45.5 ± 0.1 | 45.6 ± 0.1 | 45.7 ± 0.2 | 45.7 ± 0.2 | 45.5 ± 0.2
Mean cell hemoglobin (pg) | 15.5 ± 0.1 | 15.6 ± 0.1 | 15.4 ± 0.1 | 15.4 ± 0.1 | 15.4 ± 0.1
Mean cell hemoglobin concentration (g/dL) | 34.0 ± 0.2 | 34.2 ± 0.1 | 33.8 ± 0.2 | 33.7 ± 0.2 | 33.7 ± 0.2
Platelets (10^3^/µL) | 938 ± 49 | 992 ± 47 | 1,061 ± 54 | 1,136 ± 37** | 1,111 ± 44*
Leukocytes (10^3^/µL) | 5.14 ± 0.13 | 5.55 ± 0.29 | 5.82 ± 0.35 | 5.83 ± 0.35 | 6.07 ± 0.66
Segmented neutrophils (10^3^/µL) | 0.77 ± 0.07 | 0.85 ± 0.16 | 0.89 ± 0.08 | 0.85 ± 0.85 | 1.99 ± 0.43**
Lymphocytes (10^3^/µL) | 4.15 ± 0.11 | 4.21 ± 0.22 | 4.42 ± 0.21 | 4.54 ± 0.28 | 3.73 ± 0.27
Monocytes (10^3^/µL) | 0.10 ± 0.01 | 0.13 ± 0.01 | 0.11 ± 0.01 | 0.11 ± 0.02 | 0.10 ± 0.02
Basophils (10^3^/µL) | 0.014 ± 0.005 | 0.017 ± 0.003 | 0.017 ± 0.004 | 0.012 ± 0.002 | 0.016 ± 0.003
Eosinophils (10^3^/µL) | 0.11 ± 0.02 | 0.35 ± 0.04** | 0.39 ± 0.09** | 0.31 ± 0.06* | 0.23 ± 0.03
Female
n | 10 | 10 | 10 | 10 | 8
Hematocrit (%) | 46.9 ± 0.7 | 45.8 ± 0.6 | 45.2 ± 0.7 | 44.0 ± 0.6** | 40.9 ± 0.4**
Hemoglobin (g/dL) | 16.4 ± 0.2 | 16.0 ± 0.2 | 15.7 ± 0.2* | 15.2 ± 0.2** | 14.1 ± 0.1**
Erythrocytes (10^6^/µL) | 10.22 ± 0.14 | 9.99 ± 0.11 | 9.93 ± 0.15 | 9.70 ± 0.14** | 8.92 ± 0.08**
Reticulocytes (10^3^/µL) | 343.6 ± 15.3 | 284.2 ± 8.8* | 343.3 ± 21.5 | 307.4 ± 15.0 | 311.7 ± 27.2
Mean cell volume (fL) | 45.9 ± 0.1 | 45.9 ± 0.2 | 45.6 ± 0.1 | 45.4 ± 0.1* | 45.9 ± 0.2
Mean cell hemoglobin (pg) | 16.0 ± 0.0 | 16.0 ± 0.1 | 15.8 ± 0.1* | 15.7 ± 0.1** | 15.9 ± 0.1*
Mean cell hemoglobin concentration (g/dL) | 34.9 ± 0.1 | 34.9 ± 0.1 | 34.7 ± 0.2 | 34.5 ± 0.1 | 34.5 ± 0.2
Platelets (10^3^/µL) | 685 ± 47 | 764 ± 42 | 887 ± 64* | 960 ± 57** | 1,058 ± 43**
Leukocytes (10^3^/µL) | 5.07 ± 0.30 | 4.66 ± 0.18 | 5.56 ± 0.36 | 6.23 ± 0.30* | 6.98 ± 0.21**
Segmented neutrophils (10^3^/µL) | 0.65 ± 0.07 | 0.52 ± 0.03 | 0.80 ± 0.12 | 1.27 ± 0.14* | 1.65 ± 0.18**
Lymphocytes (10^3^/µL) | 4.15 ± 0.27 | 3.87 ± 0.17 | 4.39 ± 0.30 | 4.58 ± 0.23 | 4.90 ± 0.23*
Monocytes (10^3^/µL) | 0.11 ± 0.02 | 0.10 ± 0.01 | 0.13 ± 0.01 | 0.11 ± 0.02 | 0.12 ± 0.01
Basophils (10^3^/µL) | 0.011 ± 0.005 | 0.009 ± 0.003 | 0.022 ± 0.007 | 0.013 ± 0.004 | 0.036 ± 0.004**
Eosinophils (10^3^/µL) | 0.15 ± 0.02 | 0.17 ± 0.05 | 0.22 ± 0.04 | 0.26 ± 0.06 | 0.28 ± 0.03

* Significantly different (P ≤ 0.05) from the vehicle control group by Dunn’s or Shirley’s test.

** P ≤ 0.01.

^a^ Data are presented as mean ± standard error. Statistical tests were performed on unrounded data.