# Appendix A Summary of Nonneoplastic Lesions in Rats and Mice

Table A-1 Summary of the Incidence of Nonneoplastic Lesions in Male Rats in the Three-month Dermal Study of Cedarwood Oil^a^

| Untreated Control | Vehicle Control | 6.25% | 12.5% | 25% | 50% | 100%
Disposition Summary
Animals initially in study | 10 | 10 | 10 | 10 | 10 | 10 | 10
Early deaths
Moribund | – | – | – | – | – | – | 2
Survivors
Terminal euthanasia | 10 | 10 | 10 | 10 | 10 | 10 | 8
Animals examined microscopically | 10 | 10 | 10 | 10 | 10 | 10 | 10
Alimentary System
Esophagus | (10) | (10) | (0) | (0) | (0) | (0) | (10)
Intestine large, cecum | (10) | (10) | (0) | (0) | (0) | (0) | (10)
Intestine large, colon | (10) | (10) | (0) | (0) | (0) | (0) | (10)
Intestine large, rectum | (10) | (10) | (0) | (0) | (0) | (0) | (10)
Parasite metazoan | 1 (10%) | – | – | – | – | – | 1 (10%)
Intestine small, duodenum | (10) | (10) | (0) | (0) | (0) | (0) | (10)
Intestine small, ileum | (10) | (10) | (0) | (0) | (0) | (0) | (10)
Intestine small, jejunum | (10) | (10) | (0) | (0) | (0) | (0) | (10)
Liver | (10) | (10) | (10) | (10) | (10) | (10) | (10)
Hematopoietic cell proliferation | – | 1 (10%) | – | 1 (10%) | – | 1 (10%) | –
Hepatodiaphragmatic nodule | 1 (10%) | 1 (10%) | – | – | – | – | –
Inflammation | 8 (80%) | 8 (80%) | 10 (100%) | 10 (100%) | 7 (70%) | 7 (70%) | 9 (90%)
Necrosis, focal | – | – | – | – | – | – | 1 (10%)
Pancreas | (10) | (10) | (0) | (0) | (0) | (0) | (10)
Atrophy | – | 1 (10%) | – | – | – | – | 1 (10%)
Infiltration cellular, mononuclear cell | 4 (40%) | 5 (50%) | – | – | – | – | 3 (30%)
Salivary glands | (10) | (10) | (0) | (0) | (0) | (0) | (10)
Submandibular gland, vacuolization cytoplasmic | 5 (50%) | 2 (20%) | – | – | – | – | 4 (40%)
Stomach, forestomach | (10) | (10) | (0) | (0) | (0) | (0) | (10)
Stomach, glandular | (10) | (10) | (0) | (0) | (0) | (0) | (10)
Glands, ectasia | – | 2 (20%) | – | – | – | – | –
Cardiovascular System
Blood vessel | (10) | (10) | (0) | (0) | (0) | (0) | (10)
Heart | (10) | (10) | (0) | (0) | (0) | (0) | (10)
Cardiomyopathy | 10 (100%) | 10 (100%) | – | – | – | – | 10 (100%)
Epicardium, hyperplasia | – | – | – | – | – | – | 1 (10%)
Endocrine System
Adrenal cortex | (10) | (10) | (10) | (10) | (10) | (10) | (10)
Angiectasis | 4 (40%) | 2 (20%) | – | – | – | – | –
Adrenal medulla | (10) | (10) | (0) | (0) | (0) | (0) | (10)
Islets, pancreatic | (10) | (10) | (0) | (0) | (0) | (0) | (10)
Infiltration cellular, mononuclear cell | 1 (10%) | 1 (10%) | – | – | – | – | –
Parathyroid gland | (9) | (9) | (0) | (0) | (0) | (0) | (10)
Pituitary gland | (10) | (10) | (0) | (0) | (0) | (0) | (10)
Cyst | – | 1 (10%) | – | – | – | – | –
Thyroid gland | (10) | (10) | (10) | (10) | (10) | (10) | (10)
Ultimobranchial cyst | – | – | 2 (20%) | – | – | – | –
General Body System
None | – | – | – | – | – | – | –
Genital System
Epididymis | (10) | (10) | (0) | (0) | (0) | (0) | (10)
Infiltration cellular, mononuclear cell | – | 1 (10%) | – | – | – | – | –
Inflammation | 1 (10%) | 2 (20%) | – | – | – | – | 2 (20%)
Preputial gland | (10) | (10) | (0) | (0) | (0) | (0) | (10)
Inflammation, focal, chronic | – | 1 (10%) | – | – | – | – | 3 (30%)
Prostate | (10) | (10) | (0) | (0) | (0) | (0) | (10)
Inflammation | 2 (20%) | – | – | – | – | – | –
Seminal vesicle | (10) | (10) | (0) | (1) | (0) | (0) | (10)
Testes | (10) | (10) | (0) | (1) | (0) | (0) | (10)
Germinal epithelium, right, atrophy | – | – | – | 1 (100%) | – | – | –
Hematopoietic System
Bone marrow | (10) | (10) | (10) | (10) | (10) | (10) | (10)
Hyperplasia | – | – | – | – | – | 1 (10%) | 7 (70%)
Lymph node, mesenteric | (10) | (10) | (0) | (0) | (0) | (0) | (10)
Spleen | (10) | (10) | (0) | (0) | (0) | (0) | (10)
Hematopoietic cell proliferation | – | 1 (10%) | – | – | – | – | –
Thymus | (10) | (10) | (0) | (0) | (0) | (0) | (10)
Integumentary System
Mammary gland | (10) | (10) | (0) | (0) | (0) | (0) | (10)
Skin | (10) | (10) | (10) | (10) | (10) | (10) | (10)
Hair follicle, site of application hyperplasia | – | – | – | – | 9 (90%) | 10 (100%) | 9 (90%)
Sebaceous gland, site of application, hyperplasia | – | – | – | – | 9 (90%) | 10 (100%) | 10 (100%)
Site of application, inflammation, chronic active | – | – | 1 (10%) | 4 (40%) | 9 (90%) | 10 (100%) | 10 (100%)
Site of application, dermis, fibrosis | – | – | – | – | 7 (70%) | 10 (100%) | 10 (100%)
Site of application, epidermis, hyperkeratosis | – | – | – | 1 (10%) | 7 (70%) | 10 (100%) | 10 (100%)
Site of application, epidermis, hyperplasia | – | – | 2 (20%) | 4 (40%) | 10 (100%) | 10 (100%) | 9 (90%)
Site of application, epidermis, ulcer | – | – | – | 1 (10%) | 1 (10%) | 7 (70%) | 8 (80%)
Musculoskeletal System
Bone | (10) | (10) | (0) | (0) | (0) | (0) | (10)
Nervous System
Brain | (10) | (10) | (0) | (0) | (0) | (0) | (10)
Respiratory System
Lung | (10) | (10) | (0) | (0) | (0) | (0) | (10)
Hemorrhage | – | – | – | – | – | – | 1 (10%)
Infiltration cellular, histiocyte | 2 (20%) | 1 (10%) | – | – | – | – | 2 (20%)
Inflammation | 2 (20%) | 5 (50%) | – | – | – | – | 4 (40%)
Metaplasia, osseous | 5 (50%) | 5 (50%) | – | – | – | – | 4 (40%)
Pigmentation, hemosiderin | – | – | – | – | – | – | 1 (10%)
Serosa, inflammation, granulomatous | – | – | – | – | – | – | 1 (10%)
Nose | (10) | (10) | (0) | (0) | (0) | (0) | (10)
Inflammation, chronic active | – | – | – | – | – | – | 2 (20%)
Trachea | (10) | (10) | (0) | (0) | (0) | (0) | (10)
Special Senses System
Eye | (10) | (10) | (0) | (0) | (0) | (0) | (10)
Harderian gland | (10) | (10) | (0) | (0) | (0) | (0) | (10)
Urinary System
Kidney | (10) | (10) | (10) | (10) | (10) | (10) | (10)
Accumulation, hyaline droplet | – | – | – | – | 10 (100%) | 10 (100%) | 10 (100%)
Infiltration cellular, mononuclear cell | 1 (10%) | 1 (10%) | – | – | 1 (10%) | – | 1 (10%)
Mineralization | 9 (90%) | 4 (40%) | 7 (70%) | 9 (90%) | 8 (80%) | 8 (80%) | 8 (80%)
Nephropathy | 10 (100%) | 10 (100%) | 10 (100%) | 10 (100%) | 10 (100%) | 10 (100%) | 10 (100%)
Renal tubule, casts granular | – | – | – | – | 5 (50%) | 10 (100%) | 10 (100%)
Renal tubule, degeneration | 2 (20%) | 4 (40%) | 5 (50%) | 6 (60%) | 7 (70%) | 10 (100%) | 10 (100%)
Urinary bladder | (10) | (10) | (0) | (0) | (0) | (0) | (10)
Infiltration cellular, mononuclear cell | 1 (10%) | 1 (10%) | – | – | – | – | 1 (10%)
Serosa, mineralization, focal | – | – | – | – | – | – | 1 (10%)

^a^ Number of animals examined microscopically at the site and the number of animals with lesion.

Table A-2 Summary of the Incidence of Nonneoplastic Lesions in Female Rats in the Three-month Dermal Study of Cedarwood Oil^a^

| Untreated Control | Vehicle Control | 6.25% | 12.5% | 25% | 50% | 100%
Disposition Summary
Animals initially in study | 10 | 10 | 10 | 10 | 10 | 10 | 10
Survivors
Terminal euthanasia | 10 | 10 | 10 | 10 | 10 | 10 | 10
Animals examined microscopically | 10 | 10 | 10 | 10 | 10 | 10 | 10
Alimentary System
Esophagus | (10) | (10) | (0) | (0) | (0) | (0) | (10)
Intestine large, cecum | (10) | (10) | (0) | (0) | (0) | (0) | (10)
Intestine large, colon | (10) | (10) | (0) | (0) | (0) | (0) | (10)
Intestine large, rectum | (10) | (10) | (0) | (0) | (0) | (0) | (10)
Parasite metazoan | – | 1 (10%) | – | – | – | – | –
Intestine small, duodenum | (10) | (10) | (0) | (0) | (0) | (0) | (10)
Intestine small, ileum | (10) | (10) | (0) | (0) | (0) | (0) | (10)
Intestine small, jejunum | (10) | (10) | (0) | (0) | (0) | (0) | (10)
Liver | (10) | (10) | (10) | (10) | (10) | (10) | (10)
Hematopoietic cell proliferation | 2 (20%) | – | – | – | – | – | –
Hepatodiaphragmatic nodule | 2 (20%) | 1 (10%) | – | – | – | – | –
Inflammation | 10 (100%) | 9 (90%) | 10 (100%) | 9 (90%) | 8 (80%) | 5 (50%) | 7 (70%)
Mesentery | (0) | (0) | (1) | (0) | (0) | (0) | (0)
Mineralization | – | – | 1 (100%) | – | – | – | –
Necrosis | – | – | 1 (100%) | – | – | – | –
Fat, inflammation, granulomatous, chronic active | – | – | 1 (100%) | – | – | – | –
Pancreas | (10) | (10) | (0) | (0) | (0) | (0) | (10)
Atrophy | – | – | – | – | – | – | 1 (10%)
Infiltration cellular, mononuclear cell | 7 (70%) | 4 (40%) | – | – | – | – | 3 (30%)
Salivary glands | (10) | (10) | (0) | (0) | (10) | (10) | (10)
Sublingual gland, ectopic tissue | – | – | – | – | – | – | 1 (10%)
Submandibular gland ectopic tissue | – | – | – | – | – | – | 1 (10%)
Submandibular gland, vacuolization cytoplasmic | 3 (30%) | 4 (40%) | – | – | – | – | 1 (10%)
Stomach, forestomach | (10) | (10) | (0) | (0) | (0) | (0) | (10)
Stomach, glandular | (10) | (10) | (0) | (0) | (0) | (0) | (10)
Cardiovascular System
Blood vessel | (10) | (10) | (0) | (0) | (0) | (0) | (10)
Heart | (10) | (10) | (0) | (0) | (0) | (0) | (10)
Cardiomyopathy | 10 (100%) | 9 (90%) | – | – | – | – | 10 (100%)
Inflammation, chronic active | 1 (10%) | – | – | – | – | – | –
Endocrine System
Adrenal cortex | (10) | (10) | (0) | (0) | (0) | (0) | (10)
Infiltration cellular | 1 (10%) | – | – | – | – | – | –
Infiltration cellular, mononuclear cell | – | 1 (10%) | – | – | – | – | –
Mineralization | – | 1 (10%) | – | – | – | – | –
Adrenal medulla | (10) | (10) | (0) | (0) | (0) | (0) | (10)
Islets, pancreatic | (10) | (10) | (0) | (0) | (0) | (0) | (10)
Parathyroid gland | (9) | (9) | (0) | (0) | (0) | (0) | (10)
Pituitary gland | (10) | (10) | (0) | (0) | (0) | (0) | (10)
Cyst | 2 (20%) | 2 (20%) | – | – | – | – | 1 (10%)
Thyroid gland | (10) | (10) | (10) | (10) | (10) | (10) | (10)
Infiltration cellular, mononuclear cell | – | 2 (20%) | – | – | – | – | 1 (10%)
Ultimobranchial cyst | – | 3 (30%) | 2 (20%) | – | 3 (30%) | 3 (30%) | 2 (20%)
General Body System
None | – | – | – | – | – | – | –
Genital System
Clitoral gland | (10) | (10) | (0) | (0) | (0) | (0) | (10)
Infiltration cellular, mononuclear cell | 1 (10%) | – | – | – | – | – | –
Inflammation, focal, chronic active | 1 (10%) | – | – | – | – | – | –
Inflammation, chronic active | 1 (10%) | – | – | – | – | – | –
Ovary | (10) | (10) | (0) | (0) | (0) | (0) | (10)
Left, cyst | 1 (10%) | – | – | – | – | – | –
Uterus | (10) | (10) | (0) | (0) | (0) | (0) | (10)
Hematopoietic System
Bone marrow | (10) | (10) | (9) | (10) | (10) | (10) | (10)
Hyperplasia | – | – | – | – | 2 (20%) | 2 (20%) | 7 (70%)
Lymph node, mesenteric | (10) | (10) | (0) | (0) | (0) | (0) | (10)
Spleen | (10) | (10) | (0) | (0) | (0) | (0) | (10)
Thymus | (10) | (10) | (0) | (0) | (0) | (0) | (10)
Integumentary System
Mammary gland | (10) | (10) | (0) | (0) | (0) | (0) | (10)
Skin | (10) | (10) | (10) | (10) | (10) | (10) | (10)
Hair follicle, site of application, hyperplasia | – | – | – | 1 (10%) | 9 (90%) | 10 (100%) | 10 (100%)
Sebaceous gland, site of application, hyperplasia | – | – | – | 4 (40%) | 9 (90%) | 10 (100%) | 10 (100%)
Site of application, inflammation, chronic active | – | – | – | 7 (70%) | 10 (100%) | 10 (100%) | 10 (100%)
Site of application, dermis, fibrosis | – | – | – | 1 (10%) | 7 (70%) | 8 (80%) | 10 (100%)
Site of application, epidermis, hyperkeratosis | – | – | 1 (10%) | 5 (50%) | 10 (100%) | 10 (100%) | 10 (100%)
Site of application, epidermis, hyperplasia | – | – | 4 (40%) | 7 (70%) | 10 (100%) | 10 (100%) | 10 (100%)
Site of application, epidermis, ulcer | – | – | – | 1 (10%) | 1 (10%) | 4 (40%) | 10 (100%)
Musculoskeletal System
Bone | (10) | (10) | (0) | (0) | (0) | (0) | (10)
Nervous System
Brain | (10) | (10) | (0) | (0) | (0) | (0) | (10)
Respiratory System
Lung | (10) | (10) | (0) | (0) | (0) | (0) | (10)
Infiltration cellular, histiocyte | – | 1 (10%) | – | – | – | – | 1 (10%)
Inflammation | 3 (30%) | 2 (20%) | – | – | – | – | 2 (20%)
Metaplasia, osseous | 1 (10%) | 1 (10%) | – | – | – | – | –
Nose | (10) | (10) | (0) | (0) | (0) | (0) | (10)
Inflammation, chronic active | – | – | – | – | – | – | 1 (10%)
Vacuolization cytoplasmic | – | 1 (10%) | – | – | – | – | –
Trachea | (10) | (10) | (0) | (0) | (0) | (0) | (10)
Infiltration cellular, mononuclear cell | 1 (10%) | – | – | – | – | – | –
Special Senses System
Eye | (10) | (10) | (0) | (0) | (0) | (0) | (10)
Harderian gland | (10) | (10) | (0) | (0) | (0) | (0) | (10)
Infiltration cellular | – | – | – | – | – | – | 1 (10%)
Urinary System
Kidney | (10) | (10) | (0) | (0) | (0) | (0) | (10)
Infarct, focal, chronic | 1 (10%) | – | – | – | – | – | –
Mineralization | 5 (50%) | 5 (50%) | – | – | – | – | 6 (60%)
Nephropathy | – | 1 (10%) | – | – | – | – | 1 (10%)
Urinary bladder | (10) | (10) | (0) | (0) | (0) | (0) | (10)
Infiltration cellular, mononuclear cell | 5 (50%) | 2 (20%) | – | – | – | – | –

^a^ Number of animals examined microscopically at the site and the number of animals with lesion.

Table A-3 Summary of the Incidence of Nonneoplastic Lesions in Male Mice in the Three-month Dermal Study of Cedarwood Oil^a^

| Untreated Control | Vehicle Control | 6.25% | 12.5% | 25% | 50% | 100%
Disposition Summary
Animals initially in study | 10 | 10 | 10 | 10 | 10 | 10 | 10
Early deaths
Moribund | – | – | – | 1 | – | 1 | 10
Survivors
Terminal euthanasia | 10 | 10 | 10 | 9 | 10 | 9 | –
Animals examined microscopically | 10 | 10 | 10 | 10 | 10 | 10 | 10
Alimentary System
Esophagus | (10) | (10) | (0) | (1) | (0) | (10) | (10)
Gallbladder | (10) | (10) | (0) | (1) | (0) | (10) | (10)
Intestine large, cecum | (10) | (10) | (0) | (1) | (0) | (10) | (10)
Intestine large, colon | (10) | (10) | (0) | (1) | (0) | (10) | (10)
Intestine large, rectum | (10) | (10) | (0) | (1) | (0) | (10) | (10)
Intestine small, duodenum | (10) | (10) | (0) | (1) | (0) | (10) | (10)
Intestine small, ileum | (10) | (10) | (0) | (1) | (0) | (10) | (10)
Intestine small, jejunum | (10) | (10) | (0) | (1) | (0) | (10) | (10)
Liver | (10) | (10) | (10) | (10) | (10) | (10) | (10)
Hematopoietic cell proliferation | – | – | – | – | – | 1 (10%) | –
Infarct | – | – | – | – | – | – | 1 (10%)
Inflammation, chronic active | 8 (80%) | 7 (70%) | 6 (60%) | 8 (80%) | 7 (70%) | 2 (20%) | 1 (10%)
Necrosis, focal | – | 1 (10%) | – | – | – | 1 (10%) | 2 (20%)
Hepatocyte, depletion glycogen | – | – | – | 6 (60%) | 9 (90%) | 10 (100%) | 10 (100%)
Mesentery | (0) | (0) | (0) | (0) | (0) | (1) | (0)
Fat, fibrosis | – | – | – | – | – | 1 (100%) | –
Fat, necrosis | – | – | – | – | – | 1 (100%) | –
Pancreas | (10) | (10) | (0) | (1) | (0) | (10) | (10)
Salivary glands | (10) | (10) | (0) | (1) | (0) | (10) | (10)
Inflammation, chronic active | 1 (10%) | – | – | – | – | – | –
Stomach, forestomach | (10) | (10) | (0) | (1) | (0) | (10) | (10)
Stomach, glandular | (10) | (10) | (0) | (1) | (0) | (10) | (10)
Cardiovascular System
Blood vessel | (10) | (10) | (0) | (1) | (0) | (10) | (10)
Heart | (10) | (10) | (0) | (1) | (0) | (10) | (10)
Endocrine System
Adrenal cortex | (10) | (10) | (0) | (1) | (0) | (10) | (10)
Accessory adrenal cortical nodule | 1 (10%) | 2 (20%) | – | – | – | 2 (20%) | –
Adrenal medulla | (10) | (10) | (0) | (1) | (0) | (10) | (10)
Islets, pancreatic | (10) | (10) | (0) | (1) | (0) | (10) | (10)
Parathyroid gland | (10) | (9) | (0) | (1) | (0) | (10) | (10)
Cyst | – | 1 (11%) | – | – | – | – | 1 (10%)
Pituitary gland | (10) | (10) | (0) | (1) | (0) | (10) | (10)
Thyroid gland | (10) | (10) | (0) | (1) | (0) | (10) | (10)
Ectopic thymus | 1 (10%) | – | – | – | – | – | –
Follicle, degeneration | – | – | – | – | – | 1 (10%) | 2 (20%)
General Body System
None | – | – | – | – | – | – | –
Genital System
Coagulating gland | (10) | (10) | (0) | (1) | (0) | (10) | (10)
Epididymis | (10) | (10) | (0) | (1) | (0) | (10) | (10)
Preputial gland | (10) | (10) | (0) | (1) | (0) | (10) | (10)
Prostate | (10) | (10) | (0) | (1) | (0) | (10) | (10)
Seminal vesicle | (10) | (10) | (0) | (1) | (0) | (10) | (10)
Testes | (10) | (10) | (0) | (1) | (0) | (10) | (10)
Hematopoietic System
Bone marrow | (10) | (10) | (10) | (10) | (10) | (10) | (10)
Myeloid cell, hyperplasia | – | – | 5 (50%) | 10 (100%) | 10 (100%) | 10 (100%) | 10 (100%)
Lymph node | (0) | (0) | (0) | (0) | (0) | (0) | (9)
Axillary, hyperplasia, lymphoid | – | – | – | – | – | – | 9 (100%)
Lymph node, mandibular | (10) | (10) | (10) | (10) | (9) | (10) | (10)
Hyperplasia, lymphoid | – | – | 1 (10%) | 6 (60%) | 5 (56%) | 9 (90%) | 8 (80%)
Lymph node, mesenteric | (10) | (10) | (0) | (1) | (0) | (10) | (10)
Spleen | (10) | (10) | (10) | (10) | (10) | (10) | (10)
Hematopoietic cell proliferation | – | – | 6 (60%) | 10 (100%) | 10 (100%) | 10 (100%) | 10 (100%)
Thymus | (10) | (10) | (10) | (10) | (10) | (10) | (10)
Atrophy | – | – | – | – | 5 (50%) | 10 (100%) | 10 (100%)
Ectopic parathyroid gland | – | 1 (10%) | – | – | – | 1 (10%) | –
Integumentary System
Skin | (10) | (9) | (10) | (10) | (10) | (10) | (10)
Hair follicle, site of application, dilatation | – | – | – | – | – | 1 (10%) | 1 (10%)
Hair follicle, site of application, hyperplasia | – | – | 10 (100%) | 10 (100%) | 10 (100%) | 10 (100%) | 10 (100%)
Sebaceous gland, site of application, hyperplasia | – | – | 10 (100%) | 10 (100%) | 10 (100%) | 10 (100%) | 10 (100%)
Site of application, inflammation, chronic active | – | – | 10 (100%) | 10 (100%) | 10 (100%) | 10 (100%) | 10 (100%)
Site of application, dermis, fibrosis | – | – | 3 (30%) | 10 (100%) | 10 (100%) | 10 (100%) | 10 (100%)
Site of application, epidermis, hyperkeratosis | – | – | 7 (70%) | 10 (100%) | 10 (100%) | 10 (100%) | 10 (100%)
Site of application, epidermis, hyperplasia | – | – | 10 (100%) | 10 (100%) | 10 (100%) | 10 (100%) | 10 (100%)
Site of application, epidermis, ulcer | – | – | 2 (20%) | 8 (80%) | 10 (100%) | 9 (90%) | 10 (100%)
Musculoskeletal System
Bone | (10) | (10) | (0) | (1) | (0) | (10) | (10)
Nervous System
Brain | (10) | (10) | (0) | (1) | (0) | (10) | (10)
Respiratory System
Lung | (10) | (10) | (0) | (1) | (0) | (10) | (10)
Metaplasia, osseous | 1 (10%) | – | – | – | – | – | –
Thrombosis | – | 1 (10%) | – | – | – | – | –
Nose | (10) | (10) | (0) | (1) | (0) | (10) | (10)
Trachea | (10) | (10) | (0) | (1) | (0) | (10) | (10)
Special Senses System
Eye | (10) | (10) | (0) | (1) | (0) | (10) | (10)
Harderian gland | (10) | (10) | (0) | (1) | (0) | (10) | (10)
Urinary System
Kidney | (10) | (10) | (10) | (10) | (10) | (10) | (10)
Inflammation, chronic active | – | – | – | – | – | – | 1 (10%)
Nephropathy | – | 2 (20%) | – | 1 (10%) | 2 (20%) | 3 (30%) | 5 (50%)
Urinary bladder | (10) | (10) | (0) | (1) | (0) | (10) | (10)

^a^ Number of animals examined microscopically at the site and the number of animals with lesion.

Table A-4 Summary of the Incidence of Nonneoplastic Lesions in Female Mice in the Three-month Dermal Study of Cedarwood Oil^a^

| Untreated Control | Vehicle Control | 6.25% | 12.5% | 25% | 50% | 100%
Disposition Summary
Animals initially in study | 10 | 10 | 10 | 10 | 10 | 10 | 10
Early deaths
Moribund | – | – | – | – | – | 1 | 10
Survivors
Terminal euthanasia | 10 | 10 | 10 | 10 | 10 | 9 | –
Animals examined microscopically | 10 | 10 | 10 | 10 | 10 | 10 | 10
Alimentary System
Esophagus | (10) | (10) | (0) | (0) | (0) | (10) | (10)
Gallbladder | (10) | (10) | (0) | (0) | (0) | (10) | (10)
Intestine large, cecum | (10) | (10) | (0) | (0) | (0) | (10) | (10)
Intestine large, colon | (10) | (10) | (0) | (0) | (0) | (10) | (10)
Intestine large, rectum | (10) | (10) | (0) | (0) | (0) | (10) | (10)
Intestine small, duodenum | (10) | (10) | (0) | (0) | (0) | (10) | (10)
Intestine small, ileum | (10) | (10) | (0) | (0) | (0) | (10) | (10)
Intestine small, jejunum | (10) | (10) | (0) | (0) | (0) | (10) | (10)
Diverticulum | – | – | – | – | – | 1 (10%) | –
Liver | (10) | (10) | (10) | (10) | (10) | (10) | (10)
Infarct | – | – | – | – | – | – | 1 (10%)
Inflammation, chronic active | 10 (100%) | 10 (100%) | 8 (80%) | 9 (90%) | 9 (90%) | 10 (100%) | 8 (80%)
Tension, lipidosis | – | – | – | – | – | 1 (10%) | –
Hepatocyte, depletion glycogen | – | – | – | 5 (50%) | 9 (90%) | 10 (100%) | 10 (100%)
Hepatocyte, necrosis | – | – | – | – | – | – | 1 (10%)
Pancreas | (10) | (10) | (0) | (0) | (0) | (10) | (10)
Salivary glands | (10) | (10) | (0) | (0) | (0) | (10) | (10)
Stomach, forestomach | (10) | (10) | (0) | (0) | (0) | (10) | (10)
Stomach, glandular | (10) | (10) | (0) | (0) | (0) | (10) | (10)
Mineralization | – | 1 (10%) | – | – | – | – | –
Cardiovascular System
Heart | (10) | (10) | (0) | (0) | (0) | (10) | (10)
Endocrine System
Adrenal cortex | (10) | (10) | (0) | (0) | (0) | (10) | (10)
Accessory adrenal cortical nodule | 1 (10%) | – | – | – | – | – | –
Adrenal medulla | (10) | (10) | (0) | (0) | (0) | (10) | (10)
Islets, pancreatic | (10) | (10) | (0) | (0) | (0) | (10) | (10)
Parathyroid gland | (9) | (9) | (0) | (0) | (0) | (8) | (9)
Pituitary gland | (10) | (10) | (0) | (0) | (0) | (10) | (10)
Thyroid gland | (10) | (10) | (0) | (0) | (0) | (10) | (10)
Ectopic thymus | – | 1 (10%) | – | – | – | – | –
General Body System
None | – | – | – | – | – | – | –
Genital System
Clitoral gland | (10) | (10) | (0) | (0) | (0) | (10) | (10)
Ovary | (10) | (10) | (0) | (0) | (0) | (10) | (10)
Uterus | (10) | (10) | (0) | (0) | (0) | (10) | (10)
Decidual reaction | – | 1 (10%) | – | – | – | – | –
Endometrium, hyperplasia, cystic | 1 (10%) | 2 (20%) | – | – | – | – | –
Hematopoietic System
Bone marrow | (10) | (10) | (10) | (10) | (10) | (10) | (10)
Myeloid cell, hyperplasia | – | – | 2 (20%) | 9 (90%) | 10 (100%) | 10 (100%) | 10 (100%)
Lymph node | (0) | (0) | (0) | (0) | (1) | (2) | (10)
Hyperplasia, lymphoid | – | – | – | – | 1 (100%) | 1(50%) | –
Axillary, hyperplasia, lymphoid | – | – | – | – | – | 1 (50%) | 10 (100%)
Lymph node, mandibular | (10) | (10) | (10) | (10) | (10) | (10) | (10)
Hyperplasia, lymphoid | – | 1 (10%) | 6 (60%) | 6 (60%) | 5 (50%) | 6 (60%) | 10 (100%)
Lymph node, mesenteric | (10) | (10) | (10) | (10) | (10) | (10) | (10)
Spleen | (10) | (10) | (10) | (10) | (10) | (10) | (10)
Hematopoietic cell proliferation | 4 (40%) | 2 (20%) | 9 (90%) | 10 (100%) | 10 (100%) | 10 (100%) | 10 (100%)
Inflammation, chronic active | 1 (10%) | – | – | – | – | – | –
Thymus | (10) | (10) | (10) | (10) | (10) | (10) | (10)
Integumentary System
Mammary gland | (10) | (10) | (0) | (0) | (0) | (10) | (10)
Skin | (10) | (10) | (10) | (10) | (10) | (10) | (10)
Hair follicle, site of application, dilatation | – | – | – | – | – | – | 3 (30%)
Hair follicle, site of application, hyperplasia | – | – | 3 (30%) | 10 (100%) | 10 (100%) | 10 (100%) | 10 (100%)
Sebaceous gland, site of application, hyperplasia | 1 (10%) | – | 4 (40%) | 10 (100%) | 10 (100%) | 10 (100%) | 10 (100%)
Site of application, inflammation, chronic active | – | – | 10 (100%) | 10 (100%) | 10 (100%) | 10 (100%) | 10 (100%)
Site of application, dermis, fibrosis | – | – | 2 (20%) | 10 (100%) | 10 (100%) | 10 (100%) | 10 (100%)
Site of application, epidermis, hyperkeratosis | – | – | 2 (20%) | 10 (100%) | 10 (100%) | 10 (100%) | 10 (100%)
Site of application, epidermis, hyperplasia | – | – | 10 (100%) | 10 (100%) | 10 (100%) | 10 (100%) | 10 (100%)
Site of application, epidermis, ulcer | – | – | 2 (20%) | 6 (60%) | 9 (90%) | 10 (100%) | 10 (100%)
Musculoskeletal System
Bone | (10) | (10) | (0) | (0) | (0) | (10) | (10)
Nervous System
Brain | (10) | (10) | (0) | (0) | (0) | (10) | (10)
Respiratory System
Lung | (10) | (10) | (0) | (0) | (0) | (10) | (10)
Nose | (10) | (10) | (0) | (0) | (0) | (10) | (10)
Trachea | (10) | (10) | (0) | (0) | (0) | (10) | (10)
Special Senses System
Eye | (10) | (10) | (0) | (0) | (0) | (10) | (10)
Harderian gland | (10) | (10) | (0) | (0) | (0) | (10) | (10)
Urinary System
Kidney | (10) | (10) | (0) | (0) | (0) | (10) | (10)
Inflammation, chronic active | – | – | – | – | – | – | 2 (20%)
Nephropathy | – | – | – | – | – | 1 (10%) | –
Urinary bladder | (10) | (10) | (0) | (0) | (0) | (10) | (10)

^a^ Number of animals examined microscopically at the site and the number of animals with lesion.