# Publication Details

Publisher: National Toxicology Program

Publishing Location: Research Triangle Park, NC

ISSN: 2378-8992

DOI: https://doi.org/10.22427/NTP-TOX-85

Report Series: NTP Toxicity Report Series

Report Series Number: 85

Official citation: National Toxicology Program (NTP). 2017. NTP technical report on the toxicity studies of tetrabromobisphenol A-bis(2,3-dibromopropyl ether) (CASRN 21850-44-2) administered by gavage to F344/NTac rats and B6C3F1/N mice. Research Triangle Park, NC: National Toxicology Program. Toxicity Report 85.