# Peer Review

The draft NTP Technical Report on the Toxicity Studies of Tetrabromobisphenol A-bis(2,3-dibromopropyl ether) (CASRN 21850-44-2) Administered by Gavage to F344/NTac Rats and B6C3F1/N Mice was evaluated by the reviewers listed below. These reviewers served as independent scientists, not as representatives of any institution, company, or governmental agency. In this capacity, reviewers determined if the design and conditions of these NTP studies were appropriate and ensured that this NTP Toxicity Study Report presented the experimental results and conclusions fully and clearly.

## Peer Reviewers

- William J. Brock, Ph.D.
  Brock Scientific Consulting, LLC
  Montgomery Village, Maryland, USA
- Laura A. Hansen, Ph.D.
  Department of Biomedical Sciences
  Creighton University School of Medicine
  Omaha, Nebraska, USA
- Karen S. Regan, D.V.M.
  Regan Path/Tox Services, Inc.
  Ashland, Ohio, USA