# References

1 International Programme on Chemical Safety (IPCS). Environmental Health Criteria 172: Tetrabromobisphenol A and derivatives. Geneva, Switzerland: World Health Organization (WHO); 1995. NLM Classification: QD 181.B7. http://www.inchem.org/documents/ehc/ehc/ehc172.htm
2 United States Environmental Protection Agency (USEPA). Flame retardant alternatives for hexabromocyclododecane (HBCD). Washington, DC; 2014. EPA-740-R-14-001. https://www.epa.gov/sites/production/files/2014-06/documents/hbcd_report.pdf
3 Covaci A Harrad S Abdallah MA-E Ali N Law RJ Herzke D de Wit CA Novel brominated flame retardants: a review of their analysis, environmental fate and behaviour. Environ Int. 2011; 37(2):532–556. http://dx.doi.org/10.1016/j.envint.2010.11.007 21168217
4 United States Environmental Protection Agency (USEPA). Non-confidential 2006 IUR records by chemical, including manufacturing, processing and use information for CAS No. 21850-44-2. 2013. https://cfpub.epa.gov/iursearch/2006_iur_companyinfo.cfm?chemid=432&outchem=both
5 de Jourdan BP Hanson ML Muir DC Solomon KR Environmental fate of three novel brominated flame retardants in aquatic mesocosms. Environ Toxicol Chem. 2013; 32(5):1060–1068. http://dx.doi.org/10.1002/etc.2165 23400845
6 Qu G Liu A Wang T Zhang C Fu J Yu M Sun J Zhu N Li Z Wei G Identification of tetrabromobisphenol A allyl ether and tetrabromobisphenol A 2,3-dibromopropyl ether in the ambient environment near a manufacturing site and in mollusks at a coastal region. Environ Sci Technol. 2013; 47(9):4760–4767. http://dx.doi.org/10.1021/es3049916 23550727
7 United States Environmental Protection Agency (USEPA). An alternatives assessment for the flame retardant decabromodiphenyl ether (DecaBDE). 2014. https://www.epa.gov/sites/production/files/2014-05/documents/decabde_final.pdf
8 El-Masri HA Portier CJ Physiologically based pharmacokinetics model of primidone and its metabolites phenobarbital and phenylethylmalonamide in humans, rats, and mice. Drug Metab Dispos. 1998; 26(6):585–594. 9616196
9 Frederiksen M Vorkamp K Thomsen M Knudsen LE Human internal and external exposure to PBDEs—a review of levels and sources. Int J Hyg Environ Health. 2009; 212(2):109–134. http://dx.doi.org/10.1016/j.ijheh.2008.04.005 18554980
10 United States Environmental Protection Agency (USEPA). Polyhalogenated dibenzodioxins/furans. Appendix A: 12 chemicals in commerce requiring contaminant testing. 2013. https://www.epa.gov/oppt/chemtest/pubs/polyha2.pdf
11 United States Environmental Protection Agency (USEPA). Chemicals subject to TSCA 12(b) export notification requirements (Current as of December 11, 2012). 2013. https://www.epa.gov/oppt/import-export/pubs/12_b_listFinal-08-21-2012.pdf
12 Knudsen GA Jacobs LM Kuester RK Sipes IG Absorption, distribution, metabolism and excretion of intravenously and orally administered tetrabromobisphenol A [2,3-dibromopropyl ether] in male Fischer-344 rats. Toxicology. 2007; 237(1-3):158–167. http://dx.doi.org/10.1016/j.tox.2007.05.006 17582672
13 National Toxicology Program (NTP). Chemical disposition studies in mammals; brominated flame retardants: Tetrabromobisphenol A bis(2,3-dibromopropyl ether). Research Triangle Park, NC: University of Arizona; 2007. NIEHS Contract No. N01-ES-45529.
14 Hamers T Kamstra JH Sonneveld E Murk AJ Kester MH Andersson PL Legler J Brouwer A In vitro profiling of the endocrine-disrupting potency of brominated flame retardants. Toxicol Sci. 2006; 92(1):157–173. http://dx.doi.org/10.1093/toxsci/kfj187 16601080
15 King-Herbert A Thayer K NTP workshop: animal models for the NTP rodent cancer bioassay: stocks and strains—should we switch? Toxicol Pathol. 2006; 34(6):802–805. http://dx.doi.org/10.1080/01926230600935938 17162538
16 Battelle Columbus Operations. Biochemical toxicology report: Hepatic CYP1A1, CYP2B1, CYP1A2, and UDP GT activities for the 14-week gavage toxicity study of tetrabromobisphenol A (TBP) in Fischer F344/NTac rats (G823512-B). Columbus, OH; 2006. Battelle Study No. G823512-B.
17 Battelle Columbus Operations. Biochemical toxicology report: Hepatic CYP1A1, CYP2B1, CYP1A2, and UDP GT activities for the 14-week gavage toxicity study of tetrabromobisphenol A (TBP) in B6C3F1 mice (G823512-C). Columbus, OH; 2006. Battelle Study No. G823512-C.
18 Rutten AA Falke HE Catsburg JF Wortelboer HM Blaauboer BJ Doorn L van Leeuwen FX Theelen R Rietjens IM Interlaboratory comparison of microsomal ethoxyresorufin and pentoxyresorufin O-dealkylation determinations: standardization of assay conditions. Arch Toxicol. 1992; 66(4):237–244. http://dx.doi.org/10.1007/BF02307168 1514921
19 Liu G Gelboin HV Myers MJ Role of cytochrome P450 IA2 in acetanilide 4-hydroxylation as determined with cDNA expression and monoclonal antibodies. Arch Biochem Biophys. 1991; 284(2):400–406. http://dx.doi.org/10.1016/0003-9861(91)90315-A 1989524
20 De Vito MJ Maier WE Diliberto JJ Birnbaum LS Comparative ability of various PCBs, PCDFs, and TCDD to induce cytochrome P450 1A1 and 1A2 activity following 4 weeks of treatment. Fundam Appl Toxicol. 1993; 20(1):125–130. http://dx.doi.org/10.1006/faat.1993.1015 8432423
21 DeVito MJ Beebe LE Menache M Birnbaum LS Relationship between CYP1A enzyme activities and protein levels in rats treated with 2,3,7,8-tetrachlorodibenzo-p-dioxin. J Toxicol Environ Health. 1996; 47(4):379–394. http://dx.doi.org/10.1080/009841096161717 8600290
22 Hood A Klaassen CD Differential effects of microsomal enzyme inducers on in vitro thyroxine (T(4)) and triiodothyronine (T(3)) glucuronidation. Toxicol Sci. 2000; 55(1):78–84. http://dx.doi.org/10.1093/toxsci/55.1.78 10788562
23 Maronpot RR Boorman GA Interpretation of rodent hepatocellular proliferative alterations and hepatocellular tumors in chemical safety assessment. Toxicol Pathol. 1982;10(2):71–78. http://dx.doi.org/10.1177/019262338201000210 28094716
24 Boorman GA Montgomery CA Jr Eustis SL Wolfe MJ McConnell EE Hardisty JF Quality assurance in pathology for rodent carcinogenicity studies. In: Milman HA Weisburger EKeditors. Handbook of Carcinogen Testing. Park Ridge (NJ): Noyes Publications; 1985. p. 345–357.
25 National Toxicology Program (NTP). Toxicology studies of tetrabromobisphenol-a (CAS No. 79-94-7) in F344/NTac rats and B6C3F1/N mice and toxicology and carcinogenesis studies of tetrabromobisphenol-a in Wistar Han [Crl:WI(Han)] rats and B6C3F1/N mice (gavage studies). Research Triangle Park, NC: U.S. Department of Health and Human Services, Public Health Service, National Institutes of Health; 2014. Technical Report Series No. 587. NIH Publication No. 14-5929.
26 National Toxicology Program (NTP). Toxicology studies of p-toluenesulfonamide (CAS No. 70-55-3) administered in feed to F344/N rats, F344/NTac rats, and B6C3F1/N mice. Research Triangle Park, NC: U.S. Department of Health and Human Services, Public Health Service, National Institutes of Health; 2016. Toxicity Report Series No. 88.
27 Gart JJ Chu KC Tarone RE Statistical issues in interpretation of chronic bioassay tests for carcinogenicity. J Natl Cancer Inst. 1979;62(4):957–974. 285297
28 Dunnett CW A multiple comparison procedure for comparing several treatments with a control. J Am Stat Assoc. 1955; 50(272):1096–1121. 10.1080/01621459.1955.10501294
29 Williams DA A test for differences between treatment means when several dose levels are compared with a zero dose control. Biometrics. 1971; 27(1):103–117. http://dx.doi.org/10.2307/2528930 5547548
30 Williams DA The comparison of several dose levels with a zero dose control. Biometrics. 1972; 28(2):519–531. http://dx.doi.org/10.2307/2556164 5037867
31 Shirley E A non-parametric equivalent of Williams’ test for contrasting increasing dose levels of a treatment. Biometrics. 1977; 33(2):386–389. http://dx.doi.org/10.2307/2529789 884197
32 Williams DA A note on Shirley’s nonparametric test for comparing several dose levels with a zero-dose control. Biometrics. 1986; 42(1):183–186. http://dx.doi.org/10.2307/2531254 3719054
33 Dunn OJ Multiple comparisons using rank sums. Technometrics. 1964; 6(3):241–252. 10.1080/00401706.1964.10490181
34 Jonckheere A A distribution-free k-sample test against ordered alternatives. Biometrika. 1954; 41:133–145. 10.1093/biomet/41.1-2.133
35 Dixon W Massey F Introduction to statistical analysis. 2nd ed. New York (NY): McGraw Hill Book Company Inc; 1957. 10.2307/2332898
36 Girard DM Sager DB The use of Markov chains to detect subtle variation in reproductive cycling. Biometrics. 1987; 43(1):225–234. http://dx.doi.org/10.2307/2531963 3567307
37 Code of Federal Regulations (CFR). 21:Part 58.
38 Zeiger E Anderson B Haworth S Lawlor T Mortelmans K Salmonella mutagenicity tests: V. Results from the testing of 311 chemicals. Environ Mol Mutagen. 1992; 19 Suppl 21:2–141. http://dx.doi.org/10.1002/em.2850190603 1541260
39 MacGregor JT Wehr CM Henika PR Shelby MD The in vivo erythrocyte micronucleus test: measurement at steady state increases assay efficiency and permits integration with toxicity studies. Fundam Appl Toxicol. 1990; 14(3):513–522. http://dx.doi.org/10.1016/0272-0590(90)90255-I 2111256
40 Livingston RS Besch-Williford CL Myles MH Franklin CL Crim MJ Riley LK Pneumocystis carinii infection causes lung lesions historically attributed to rat respiratory virus. Comp Med. 2011; 61(1):45–59. 21819681
41 Damsch S Eichenbaum G Tonelli A Lammens L Van den Bulck K Feyen B Vandenberghe J Megens A Knight E Kelley M Gavage-related reflux in rats: identification, pathogenesis, and toxicological implications (review). Toxicol Pathol. 2011; 39(2):348–360. http://dx.doi.org/10.1177/0192623310388431 21422261
42 Carson F Hladik C Histotechnology: A self-instructional text. 3rd ed. Hong Kong, China: American Society for Clinical Pathology; 2009.
43 National Toxicology Program (NTP). Toxicology studies of a pentabromodiphenyl ether mixture [DE-71 (technical grade)] (CAS No. 32534-81-9) in F344/N rats and B6C3F1/N mice and toxicology and carcinogenesis studies of a pentabromodiphenyl ether mixture [DE-71 (technical grade)] in Wistar Han [Crl:WI(Han)] rats and B6C3F1/N mice (gavage studies). Research Triangle Park, NC: U.S. Department of Health and Human Services, Public Health Service, National Institutes of Health; 2016. Technical Report Series No. 589.
44 National Toxicology Program (NTP). Toxicology and carcinogenesis studies of 2,3-dibromo-1-propanol (CAS No. 96-13-9) in F344/N rats and B6C3F1 mice (dermal studies). Research Triangle Park, NC: U.S. Department of Health and Human Services, Public Health Service, National Institutes of Health; 1993. Technical Report Series No. 400. NIH Publication No. 94-2855.
45 Standard Infrared Grating Spectra Spectrum 66767 K. Vol. 75. Philadelphia (PA): Sadtler Research Laboratories, Division of Bio-Rad Laboratories, Inc; 1984.
46 Standard NMR Spectrum 39539 M. Vol. 70. Philadelphia (PA): Sadtler Research Laboratories, Division of Bio-Rad Laboratories, Inc; 1984. (Spectra).