# Discussion

The current tetrabromobisphenol A-bis(2,3-dibromopropyl ether) 3-month F344/NTac rat and B6C3F1/N mouse studies were performed to evaluate the toxic potential of this flame retardant and to compare the toxicity of the test chemical to that of the structurally related flame retardant tetrabromobisphenol A.^25^

In these 3-month tetrabromobisphenol A-bis(2,3-dibromopropyl ether) studies, there were no treatment-related mortality or clinical signs in F344/NTac rats or B6C3F1/N mice, and final mean body weights of dosed groups were within 10% of those of the vehicle controls, except for 250 mg/kg female mice.

Two types of lung lesions were seen in rats treated with tetrabromobisphenol A-bis(2,3-dibromopropyl ether). The first lung lesion, granulomatous inflammation, was seen in all treated rat groups, but the severity of this lesion did not increase with increased tetrabromobisphenol A-bis(2,3-dibromopropyl ether) exposure. This lung lesion was characterized by foci of vacuolated mononuclear and occasionally multinucleated macrophages within the alveolar lumens and less often in the terminal bronchioles. At times, these macrophages had linear clear spaces consistent with sterol clefts and/or small, pale yellow, round refractile globules, which may have been corn oil. Special studies were performed to determine the pathogenesis of this lesion. Evaluation of the nasal cavity, larynx, and trachea revealed no histologic lesions, ruling out gavage-related reflux as a potential etiology.^41^ Because H&E evaluation revealed foreign material consistent with corn oil within the granulomatous foci, Sudan black was used to better characterize this lesion. Sudan black is a dye that is commonly used to stain lipids. In the animals evaluated, this foreign material did stain with Sudan black, indicating that it was most likely the corn oil vehicle. Select lung tissue from Wistar Han rats at the 3-month interim evaluation in the 2-year corn oil gavage study of tetrabromobisphenol A^25^ were also evaluated with Sudan black. Although no similar granulomatous lesions were present, there was occasional foreign material, morphologically consistent with corn oil, which was Sudan black positive. This suggests that small amounts of corn oil can be aspirated and not necessarily result in histologic lesions. Select lung tissue from rats in the 3-month p-toluenesulfonamide feed study^26^ were evaluated as well, and not surprisingly, there were no granulomatous lesions, no similar foreign material (small pale yellow refractile globules) and no Sudan black positive foreign material. One additional study looked at lungs from mice in the current study of tetrabromobisphenol A-bis(2,3-dibromopropyl ether), and there were no granulomatous lesions, no foreign material, and no conclusive Sudan black positivity. The reason for this lack of similar effects in mice is unknown and may be multifactorial. Potential factors may include superior gavage techniques in the mouse study and/or the smaller gavage needle bore/diameters used for the mice.

Based on the presence of a Sudan black positive foreign lipid material associated with the granulomatous lesions in the affected rats in this study, it is suggested that this material was corn oil vehicle aspirated during the gavage process and was not due to a systemic effect of tetrabromobisphenol A-bis(2,3-dibromopropyl ether). However, because corn oil was seen in the lungs of some rats from the tetrabromobisphenol A study without an inflammatory component,^25^ and this granulomatous lesion did not occur in the vehicle control rats from the current tetrabromobisphenol A-bis(2,3-dibromopropyl ether) study, it may be that test article was also present in the aspirated material and this may have caused the granulomatous response in the lung. Accordingly, the occurrence of this granulomatous lung lesion was most likely caused by the procedure of administering the test article to rats that resulted in a small amount of gavage material (corn oil and test article) remaining on the gavage needle during removal resulting in a localized, topical contact with the chemical. High viscosity of the corn oil gavage solution may have caused the material to adhere to the gavage needles. Because oral intubation of mice is somewhat more difficult compared to rats, the rate of dose administration for mice is accordingly slower. The slower rate of administration (and, therefore, no deposition of the gavage material in the lung) could explain the lack of pulmonary lesions in the mice.

The second lung lesion seen in the rats was chronic inflammation, and it was seen in vehicle control and treated rats. This lesion was morphologically different from the lesion associated with aspiration of gavage solution and was in a different location within the lung. The granulomatous lesions were within the alveoli lumens, and less often in the terminal bronchioles, with minimal to no perivascular involvement. The chronic inflammatory lesions were confined to the perivascular regions. No Sudan black positive material was identified within these perivascular chronic inflammatory lesions.

The chronic inflammatory lung lesions were characterized by dense perivascular accumulations of mostly lymphocytes with fewer macrophages, granulocytes, and erythrocytes. The morphology of this rat lung lesion is characteristic of Pneumocystis carinii infection.^40^ In immunocompetent rats, infection with the fungus P. carinii causes an infectious interstitial pneumonia characterized by dense perivascular cuffs of primarily lymphocytes and a lymphohistiocytic interstitial pneumonia. This lesion has been reported in research rats since the 1990s and was previously attributed to “rat respiratory virus” with an unknown etiology. In 2011, Livingston et al.^40^ determined that the etiologic agent was P. carinii. In immunocompetent animals, there are usually no clinical signs associated with this infection and it is considered self-limiting, resolving by about 20 weeks of age. Historically, this organism had been undetectable with silver stains and thus was undiagnosed in rat colonies until 2011 when Livingston et al.^40^ used polymerase chain reaction (PCR) to detect the presence of this specific fungus. Since that time, both PCR and serological tests have been used to detect P. carinii. The exact etiology of the lung lesions in the current study remains uncertain because the NTP rat colonies and sentinel animals were not tested for this organism. At the time this study was performed the causative agent for “rat respiratory virus” had not been determined, hence there was no assay for the disease. However, due to the morphology of the lesions and the age of the rats, the most likely etiology is P. carinii.

In the current NTP study, there were no tetrabromobisphenol A-bis(2,3-dibromopropyl ether) treatment-related changes in thyroxine, triiodothyronine, or thyroid stimulating hormone levels in rats (not measured in mice), while with tetrabromobisphenol A,^25^ there were decreases in thyroxine levels in F344/NTac rats after 4, 23, and 93 days of chemical administration.

Tetrabromobisphenol A-bis(2,3-dibromopropyl ether) was negative in bacterial mutagenicity tests (Table E-1) consistent with what has been seen previously with tetrabromobisphenol A and other brominated flame retardants.^25,43^ In tests with other brominated chemicals, cancer target organs are not always identified in 3-month studies. For example, tetrabromobisphenol A induced uterine adenocarcinomas in the 2-year rat study, but uterus was not identified as a target organ in the 3-month rat study, based on the absence of treatment-related lesions.^25^ Similarly, in a 2-year 2,3-dibromo-1-propanol study, intestinal tumors were seen in rats, but the intestine was not designated a target organ in the 3-month study.^44^ Thus, while the current tetrabromobisphenol A-bis(2,3-dibromopropyl ether) study did not result in treatment-related target organ toxicity in either rats or mice, it is uncertain if this result would predict positive or negative carcinogenic activity after longer term administration of tetrabromobisphenol A-bis(2,3-dibromopropyl ether).

Under the conditions of these 3-month gavage studies, there were no clinical findings or treatment-related lesions in male or female F344/NTac rats or B6C3F1/N mice administered tetrabromobisphenol A-bis(2,3-dibromopropyl ether) at 0, 62.5, 125, 250, 500, or 1,000 mg/kg in rats or 0, 125, 250, 500, 1,000, or 2,000 mg/kg in mice. Final mean body weights of treated rats and mice were generally within 10% of vehicle controls, and there were no treatment-related effects on organ weights.