# Results

## Three-month Study in Rats

All rats survived to the end of the study with the exception of two 62.5 mg/kg males and one vehicle control female; one male death was due to a dosing accident (Table 2). Final mean body weights and body weight gains of male and female rats were similar to those of the vehicle controls (Table 2; Figure 2). No treatment-related clinical findings or treatment-related gross lesions were identified in males or females.

Table 2 Survival and Body Weights of Rats in the Three-month Gavage Study of Tetrabromobisphenol A-bis(2,3-dibromopropyl ether)^a^

Dose (mg/kg) | Survival^b^ | Initial Body Weight (g) | Final Body Weight (g) | Change in Body Weight (g) | Final Weight Relative to Controls (%)
Male
0 | 10/10 | 85 ± 3 | 330 ± 9 | 244 ± 9
62.5 | 8/10^c^ | 85 ± 2 | 344 ± 8 | 258 ± 8 | 104
125 | 10/10 | 85 ± 3 | 329 ± 7 | 245 ± 7 | 100
250 | 10/10 | 84 ± 2 | 342 ± 6 | 257 ± 6 | 104
500 | 10/10 | 86 ± 3 | 333 ± 5 | 247 ± 6 | 101
1,000 | 10/10 | 86 ± 3 | 320 ± 8 | 234 ± 8 | 97
Female
0 | 9/10^d^ | 83 ± 2 | 191 ± 4 | 108 ± 4
62.5 | 10/10 | 83 ± 1 | 195 ± 4 | 112 ± 4 | 102
125 | 10/10 | 83 ± 2 | 188 ± 4 | 106 ± 4 | 98
250 | 10/10 | 83 ± 1 | 194 ± 4 | 111 ± 4 | 101
500 | 10/10 | 84 ± 2 | 188 ± 3 | 104 ± 3 | 98
1,000 | 10/10 | 83 ± 2 | 190 ± 4 | 106 ± 3 | 99

^a^ Weights and weight changes are given as mean ± standard error. Subsequent calculations are based on animals surviving to the end of the study. Differences from the vehicle control group are not significant by Dunnett’s test.

^b^ Number of animals surviving at 14 weeks/number initially in group.

^c^ One 62.5 mg/kg male died early of a natural death on test day 37 and had lesions of minimal cardiomyopathy, minimal chronic liver inflammation, minimal liver cytoplasmic vacuolization, and acute and minimal pulmonary inflammation. Another 62.5 mg/kg male died of a dosing accident on test day 40 and had lesions of minimal cardiomyopathy, minimal renal nephropathy and mineralization, minimal chronic liver cytoplasmic vacuolization, mesenteric lymph node moderate histiocytic cellular infiltration, and acute mild pulmonary inflammation.

^d^ Week of death: 8.

Figure 2

Growth Curves for Rats Administered Tetrabromobisphenol A-bis(2,3-dibromopropyl ether) by Gavage for Three Months

Small (≤15%) decreases in cholesterol concentrations occurred in the 250 mg/kg or greater male and female rats (Table B-1). This effect was observed in one or more of the higher dose groups at all time points, albeit inconsistently within a dosed group. Only the 500 mg/kg female rats demonstrated decreases at all time points. The toxicologic relevance of these small, inconsistent decreases in circulating cholesterol concentrations is unknown, but could suggest some small alteration in cholesterol metabolism related to treatment.

Liver enzyme levels showed an apparent decrease in treated groups of males and females when normalized on a microsomal protein level (Table F-1). However, this decrease in liver enzyme levels was not considered to be biologically relevant because the absolute values for the liver enzymes did not increase with treatment.

There were no chemical-related effects on absolute or relative organ weights in males or females (Table C-1).

There were no changes in the number of sperm or spermatids, sperm motility, or testis or epididymis weights of dosed males (Table D-1). There were no estrous cycle changes in dosed females (Table D-2, Table D-3, Figure D-1). Under the conditions of this study, gavage administration of tetrabromobisphenol A-bis(2,3-dibromopropyl ether) did not exhibit the potential to be a reproductive toxicant in male or female rats.

In the lung, incidences of granulomatous inflammation in 62.5, 125, 250, and 500 mg/kg males and in females administered 125 mg/kg or greater were significantly greater than those in the vehicle control groups (Table 3, Table A-1, Table A-2). The incidences of chronic active inflammation were significantly increased in 250 mg/kg or greater females; the incidence of this lesion was significantly decreased in 62.5 mg/kg males.

Table 3 Incidences of Nonneoplastic Lesions of the Lung in Rats in the Three-month Gavage Study of Tetrabromobisphenol A-bis(2,3-dibromopropyl ether)

| Vehicle Control | 62.5 mg/kg | 125 mg/kg | 250 mg/kg | 500 mg/kg | 1,000 mg/kg
Male
Number Examined
Microscopically | 10 | 10 | 10 | 10 | 10 | 10
Inflammation, Granulomatous^a^ | 0 | 4* (1.5)^b^ | 8** (1.6) | 8** (1.4) | 6** (1.0) | 2 (1.5)
Inflammation, Chronic Active | 7 (1.1) | 1** (1.0) | 9 (2.3) | 6 (1.0) | 8 (1.1) | 7 (1.1)
Female
Number Examined
Microscopically | 10 | 10 | 10 | 10 | 10 | 10
Inflammation, Granulomatous | 0 | 3 (1.3) | 6** (1.5) | 6** (1.5) | 6** (1.0) | 5* (1.4)
Inflammation, Chronic Active | 1 (1.0) | 4 (1.0) | 3 (1.7) | 6* (1.2) | 6* (1.2) | 8** (1.4)

* Significantly different (P ≤ 0.05) from the vehicle control group by the Fisher exact test.

** P ≤ 0.01.

^a^ Number of animals with lesion.

^b^ Average severity grade of lesions in affected animals: 1 = minimal, 2 = mild, 3 = moderate, 4 = marked.

Granulomatous inflammation in the lung of male and female rats was characterized by foci of vacuolated mononuclear and occasionally multinucleated macrophages within the alveoli lumens, and less often in the terminal bronchioles, with minimal to no perivascular involvement. Some macrophages contained linear clear spaces consistent with sterol clefts and others contained small refractile globules, consistent with oil droplets.

Chronic active inflammation in the lung of male and female rats was characterized by dense perivascular accumulations of lymphocytes with fewer macrophages, granulocytes, and erythrocytes. This lesion is morphologically consistent with Pneumocystis carinii infection.^40^

### Three-month Study in Mice

All mice survived to the end of the study (Table 4). The final mean body weights and body weight gains of all dosed groups of males were similar to those of the vehicle control group; the final mean body weight of 250 mg/kg females was 11% greater than that of the vehicle controls, and the mean body weight gain of this group was significantly increased (Table 4; Figure 3). No treatment-related clinical findings or treatment-related gross lesions were identified in males or females.

Table 4 Survival and Body Weights of Mice in the Three-month Gavage Study of Tetrabromobisphenol A-bis(2,3-dibromopropyl ether)^a^

Dose (mg/kg) | Survival^b^ | Initial Body Weight (g) | Final Body Weight (g) | Change in Body Weight (g) | Final Weight Relative to Controls (%)
Male
0 | 10/10 | 23.3 ± 0.4 | 36.8 ± 1.0 | 13.5 ± 0.9
125 | 10/10 | 23.2 ± 0.4 | 39.0 ± 0.9 | 15.9 ± 0.6 | 106
250 | 10/10 | 23.0 ± 0.3 | 38.3 ± 1.0 | 15.3 ± 0.7 | 104
500 | 10/10 | 23.4 ± 0.4 | 39.4 ± 1.5 | 16.0 ± 1.1 | 107
1,000 | 10/10 | 23.0 ± 0.3 | 38.2 ± 0.9 | 15.2 ± 0.7 | 104
2,000 | 10/10 | 22.8 ± 0.3 | 39.1 ± 1.1 | 16.3 ± 0.9 | 106
Female
0 | 10/10 | 18.4 ± 0.4 | 29.2 ± 1.0 | 10.9 ± 0.7
125 | 10/10 | 18.7 ± 0.3 | 31.6 ± 1.3 | 12.9 ± 1.0 | 108
250 | 10/10 | 18.6 ± 0.3 | 32.4 ± 0.7 | 13.8 ± 0.5* | 111
500 | 10/10 | 18.5 ± 0.3 | 31.0 ± 0.8 | 12.5 ± 0.7 | 106
1,000 | 10/10 | 18.8 ± 0.3 | 31.0 ± 0.8 | 12.2 ± 0.7 | 106
2,000 | 10/10 | 18.5 ± 0.3 | 30.2 ± 0.9 | 11.7 ± 0.7 | 103

* Significantly different (P ≤ 0.05) from the vehicle control group by Dunnett’s test.

^a^ Weights and weight changes are given as mean ± standard error.

^b^ Number of animals surviving at 14 weeks/number initially in group.

Figure 3

Growth Curves for Mice Administered Tetrabromobisphenol A-bis(2,3-dibromopropyl ether) by Gavage for Three Months

No changes attributable to administration of tetrabromobisphenol A-bis(2,3-dibromopropyl ether) occurred in the hematology data for mice (Table B-2).

Liver enzyme levels showed an apparent decrease in treated groups of males and females when normalized on a microsomal protein level (Table F-2). However, this decrease in liver enzyme levels was not considered to be biologically relevant because the absolute values for the liver enzymes did not increase with treatment.

There were no chemical-related effects on absolute or relative organ weights in males or females (Table C-2).

There were no changes in the number of sperm or spermatids, sperm motility, or testis or epididymis weights of dosed males (Table D-4). There were no estrous cycle changes in dosed females (Table D-5, Table D-6, Figure D-2). Under the conditions of this study, gavage administration of tetrabromobisphenol A-bis(2,3-dibromopropyl ether) did not exhibit the potential to be a reproductive toxicant in male or female mice.

There were no gross or histologic lesions that were considered treatment related (Table A-3, Table A-4).

## Special Respiratory System Microscopic Review

Special NTP reviews (1 through 5) of respiratory system tissues of rats and mice were conducted to better define and determine the nature of the pulmonary granulomatous and chronic active inflammatory lesions that occurred in the lungs of rats in the current study.

In Review 1, histologic evaluation of H&E stained sections of the nasal cavity, larynx, and trachea from all male and female vehicle control and treated rats in the current study was conducted to determine if gavage-related reflux could have caused the granulomatous lesions.^41^ No significant treatment-related histologic lesions were noted in any of the tissues examined.

In Review 2, Sudan black stained sections of the lung from three vehicle control and three dosed F344/NTac rats in the current study were evaluated to determine if corn oil could be present in the lung and, if so, was it present within the granulomatous lesions. Sudan black is a diazo dye used for the staining of some lipoproteins in paraffin sections.^42^ The presence of granulomatous inflammation correlated with the presence of Sudan black positive material within the distal alveolar spaces. This positive staining correlated with the small round globules, consistent with oil droplets, that were noted with H&E stain.

In Review 3, H&E and Sudan black stained sections of lung from five vehicle control Wistar Han rats and five high dose Wistar Han rats at the 3-month interim evaluation in the 2-year corn oil gavage study of tetrabromobisphenol A^25^ were examined for granulomatous inflammation and corn oil droplets. Animals from that tetrabromobisphenol A study were used because that study was conducted at the same laboratory at approximately the same time as the current tetrabromobisphenol A-bis(2,3-dibromopropyl ether) study, tetrabromobisphenol A is a related chemical, and the route of administration was the same. Granulomatous lesions similar to those that occurred in F344/NTac rats in the current tetrabromobisphenol A-bis(2,3-dibromopropyl ether) study were not present in any of the tetrabromobisphenol A Wistar Han rat lungs examined, but occasional similar pale yellow, small refractile, round globules (consistent with oil droplets) were present without an inflammatory response. In addition, there was a correlation between the Sudan black positive material in the alveolar spaces with the presence of this pale yellow material on H&E staining in the lung tissues from Wistar Han rats in the tetrabromobisphenol A study.

Review 4 involved an evaluation of select H&E and Sudan black stained sections of lungs from five control and five high dose F344/NTac rats from the 3-month feed study of p-toluenesulfonamide^26^ for similar granulomatous lesions. The rationale for comparing animals from a feed study to those from the current gavage study was to determine if the granulomatous lung lesions in the current study were due to corn oil aspiration. There was an absence of granulomatous lesions similar to those observed in the lungs of rats treated with tetrabromobisphenol A-bis(2,3-dibromopropyl ether) in the current study, and no evidence of Sudan black positive material in any of the animals examined. In addition, there were fewer numbers of alveolar macrophages and intra-alveolar debris in the rats from the feed study compared to those from the current gavage study.

In Review 5, Sudan black stained sections of lung from six select vehicle control (i.e., corn oil) and six high dose B6C3F1/N mice in the current gavage study of tetrabromobisphenol A-bis(2,3-dibromopropyl ether) were examined. The rationale for using tetrabromobisphenol A-bis(2,3-dibromopropyl ether) treated mice was to determine if corn oil was present in mice treated with tetrabromobisphenol A-bis(2,3-dibromopropyl ether) as was found in tetrabromobisphenol A-bis(2,3-dibromopropyl ether) treated rats. Only one mouse had questionable Sudan black positive material, however, granulomatous lesions similar to those present in the rat lungs did not occur.

## Genetic Toxicology

Tetrabromobisphenol A-bis(2,3-dibromopropyl ether) was tested for mutagenicity in three strains of Salmonella typhimurium (TA98, TA100, and TA102), with and without 10% rat liver S9 mix. The sample of tetrabromobis-phenol A-bis(2,3-dibromopropyl ether) (lot 324811) that was used in the mutagenicity studies was not the same lot that was used in the 3-month gavage studies in rats and mice. Tetrabromobisphenol A-bis(2,3-dibromopropyl ether) (dose range of 100 to 10,000 µg/plate) showed no evidence of mutagenic activity in any of the three tester strains, with or without S9 (Table E-1).

In vivo, no significant increases in the frequencies of micronucleated normochromatic erythrocytes were observed in peripheral blood samples from male or female mice from the 3-month gavage study (Table E-2). Furthermore, no significant changes in the percentage of polychromatic erythrocytes among total red blood cells were seen in these mice, suggesting that tetrabromobisphenol A-bis(2,3-dibromopropyl ether) did not induce bone marrow toxicity under the conditions of this study.