# Materials and Methods

## Procurement and Characterization

### Tetrabromobisphenol A-bis(2,3-dibromopropyl ether)

Tetrabromobisphenol A-bis(2,3-dibromopropyl ether) was obtained from Great Lakes Chemical Corporation (West Lafayette, IN) in one lot (534106) that was used during the 3-month studies. Identity and purity analyses were conducted by the analytical chemistry laboratory at Midwest Research Institute (Kansas City, MO), and the study laboratory at Battelle Columbus Operations (Columbus, OH) conducted additional identity analyses and confirmed purity (Appendix G). Reports on analyses performed in support of the tetrabromobisphenol A-bis(2,3-dibromopropyl ether) studies are on file at the National Institute of Environmental Health Sciences.

The chemical, a white powder, was identified as tetrabromobisphenol A-bis(2,3-dibromopropyl ether) using infrared and proton nuclear magnetic resonance spectroscopy. Melting point analysis by differential scanning calorimetry indicated that lot 534106 of the test article contained impurities. The purity of lot 534106 was determined by high-performance liquid chromatography (HPLC) with ultraviolet (UV) detection; 12 reportable impurities with a total relative peak area of approximately 5.8% were detected. One impurity (approximately 2% relative to the total peak area) was tentatively identified as 1,3-dibromo-2-{[(2E)-3-bromoprop-2-en-1-yl]oxy}-5-{1-[3,5-dibromo-4-(2,3-dibromopropoxy)phenyl]-1-methylethyl}benzene using liquid chromatography coupled with mass spectrometry. The overall purity of lot 534106 was determined to be approximately 94%.

To ensure stability, the bulk chemical was stored at room temperature (~25°C) in amber glass bottles. Periodic reanalyzes of the bulk chemical were performed by the study laboratory during the 3-month studies using HPLC/UV, and no degradation of the test article was detected.

### Corn Oil

Corn oil was obtained in two lots (UU0854 and UW0493) from Spectrum Chemicals and Laboratory Products (Gardena, CA) and was used as the vehicle in the 3-month studies. Periodic analyses of the corn oil vehicle performed by the study laboratory using potentiometric titration demonstrated peroxide concentrations less than the rejection level of 3 mEq/kg.

## Preparation and Analyses of Dose Formulations

The dose formulations were prepared four times by mixing tetrabromobisphenol A-bis(2,3-dibromopropyl ether) with corn oil to give the required concentrations (Table G-1). Homogeneity studies of 1.0 and 600 mg/mL formulations and stability studies of the 1.0 mg/mL formulation were performed by the analytical chemistry laboratory using HPLC/UV; the study laboratory used the same analytical system to perform additional homogeneity studies of 12.5, 25, 50, 400, and 800 mg/mL formulations and a gavageability study of a 200 mg/mL dose formulation. Homogeneity was deemed acceptable for all of the formulations; stability was confirmed for at least 42 days for dose formulations stored in sealed glass containers at temperatures up to 25°C, and for 3 hours under simulated animal room conditions. Gavageability of the 200 mg/mL dose formulation was confirmed by the study laboratory.

Analyses of the dose formulations of tetrabromobisphenol A-bis(2,3-dibromopropyl ether) were conducted three times by the study laboratory using HPLC/UV; animal room samples of these dose formulations were also analyzed (Table G-2). Fourteen of the 15 dose formulations for rats and mice were within 10% of the target concentrations; 14 of 18 animal room samples for rats and 12 of 15 for mice were within 10% of the target concentrations.

## Animal Source

Male and female F344/NTac rats were obtained from the commercial colony at Taconic Farms, Inc. (Germantown, NY), and B6C3F1/N mice were obtained from the NTP colony at Taconic Farms, Inc. The rationale for change of rat strain from F344/N to F344/NTac was a programmatic decision. For many years, NTP used the inbred F344/N rat for its toxicity and carcinogenicity studies. Over a period of time, the F344/N rat exhibited sporadic seizures and idiopathic chylothorax, and consistently high rates of mononuclear cell leukemia and testicular neoplasia. Because of these issues in the F344/N rat and NTP’s desire to find a more fecund rat model that could be used in both reproductive and carcinogenesis studies for comparative purposes, a change in the rat model was explored. Following a workshop in 2005, the F344 rat from the Taconic commercial colony (F344/NTac) was used for a few NTP studies to allow NTP to evaluate different rat models. The F344/NTac rat was used in four subchronic and two chronic studies between 2005 and 2006.^15^

## Animal Welfare

Animal care and use are in accordance with the Public Health Service Policy on Humane Care and Use of Animals. All animal studies were conducted in an animal facility accredited by the Association for the Assessment and Accreditation of Laboratory Animal Care International. Studies were approved by the Battelle Columbus Operations Animal Care and Use Committee and conducted in accordance with all relevant NIH and NTP animal care and use policies and applicable federal, state, and local regulations and guidelines.

## Three-month Studies

On receipt, the rats were 3 to 4 weeks old and the mice were 4 to 5 weeks old. Animals were quarantined for 11 to 14 days; rats were 5 to 6 weeks old and mice were 6 to 7 weeks old on the first day of the studies. Before the studies began, five male and five female rats and mice were randomly selected for parasite evaluation and gross observation for evidence of disease. The health of the animals was monitored during the studies using the protocols of the NTP Sentinel Animal Program (Appendix I); all test results were negative.

Recommended doses for the NTP subchronic studies in rats and mice were 0, 125, 250, 500, and 1,000 mg/kg (corn oil gavage). These doses were based on the relatively low toxicity reported for this chemical in the literature^1^ and the NTP finding that the maximum amount of chemical that could be gavaged was 1,000 mg/kg due to viscosity. Corn oil gavage was selected as the route of administration because oral exposure is a likely route of exposure in humans, and to allow for comparison of results with those of other flame retardants administered by this route.

Core study groups of 10 male and 10 female rats were administered tetrabromobisphenol A-bis(2,3-dibromopropyl ether) in corn oil by gavage at doses of 0, 62.5, 125, 250, 500, or 1,000 mg/kg body weight 5 days per week for 14 weeks, and additional groups of 10 male and 10 female special study rats were administered the same doses for 23 days for hematology, clinical chemistry, and liver enzyme level determinations. Groups of 10 male and 10 female mice were administered 0, 125, 250, 500, 1,000, or 2,000 mg/kg for 14 weeks. Vehicle control animals received the corn oil vehicle alone. Dosing volumes were 5 mL/kg for rats and 10 mL/kg for mice. Feed and water were available ad libitum. Rats and female mice were housed five per cage, and male mice were housed individually. Clinical findings were recorded postdosing on day 1, weekly, and at the end of the studies; animals were weighed on day 1, weekly, and at the end of the studies. Details of the study design and animal maintenance are summarized in Table 1.

Table 1 Experimental Design and Materials and Methods in the Three-month Gavage Studies of Tetrabromobisphenol A-bis(2,3-dibromopropyl ether)

Three-month Studies
Study Laboratory
Battelle Columbus Operations (Columbus, OH)
Strain and Species
F344/NTac rats B6C3F1/N mice
Animal Source
Taconic Farms, Inc. (Germantown, NY)
Time Held Before Studies
Rats: 11 (males) or 12 (females) days Mice: 13 (females) or 14 (males) days
Average Age When Studies Began
Rats: 5 to 6 weeks Mice: 6 to 7 weeks
Date of First Dose
Rats: January 9 (males) or 10 (females), 2006 Mice: January 11 (females) or 12 (males), 2006
Duration of Dosing
5 days per week for 14 weeks
Rats: April 10 (males) or 11 (females), 2006 Mice: April 12 (females) or 13 (males), 2006
Necropsy Dates
Rats: April 11 (males) or 12 (females), 2006 Mice: April 13 (females) or 14 (males), 2006
Average Age at Necropsy
Rats: 18 to 19 weeks Mice: 19 to 20 weeks
Size of Study Groups
Core study animals: 10 males and 10 females (rats and mice)
Special study animals: 10 males and 10 females (rats only)
Method of Distribution
Animals were distributed randomly into groups of approximately equal initial mean body weights.
Animals per Cage
5 (rats and female mice) or 1 (male mice)
Method of Animal Identification
Tail tattoo
Diet
Irradiated NTP-2000 open formula wafer feed (Zeigler Brothers, Inc., Gardners, PA), available ad libitum; changed at least weekly
Water
Tap water (City of Columbus municipal supply) via automatic watering system (Edstrom Industries, Waterford, WI), available ad libitum
Cages
Polycarbonate (Lab Products, Inc., Seaford, DE), changed weekly (male mice) or twice weekly (rats and female mice)
Bedding
Irradiated Sani Chips^®^ (P.J. Murphy Forest Products Corp., Montville, NJ), changed weekly (male mice) or twice weekly (rats and female mice)
Rack Filters
Spun-bonded polyester (Snow Filtration Co., Cincinnati, OH) changed every 2 weeks
Racks
Stainless steel (Lab Products, Inc., Seaford, DE), changed every 2 weeks
Animal Room Environment
Temperature: 72° ± 3°F Relative humidity: 50% ± 15% Room fluorescent light: 12 hours/day Room air changes: at least 10/hour
Doses
Rats: 0, 62.5, 125, 250, 500, or 1,000 mg/kg in corn oil (dosing volume, 5 mL/kg) Mice: 0, 125, 250, 500, 1,000, or 2,000 mg/kg in corn oil (dosing volume, 10 mL/kg)
Type and Frequency of Observation
Observed twice daily; animals were weighed and clinical findings were recorded on day 1, weekly thereafter, and at the end of the studies.
Method of Euthanasia
Carbon dioxide asphyxiation (special study rats and mice) or exsanguination by severing portal vein (core study rats)
Necropsy
Necropsies were performed on all core study rats and mice. Organs weighed were heart, right kidney, liver, lung, spleen, right testis, and thymus.
Clinical Pathology
Blood was collected from the retroorbital plexus of special study rats on days 4 and 23 and of core study rats and mice at the end of the studies; blood was also collected from the heart of core study rats at the end of the study. Hematology parameters were measured on day 23 (rats) and at the end of the studies (rats and mice). Clinical chemistry and thyroid hormones were measured in rats on days 4 (except triiodothyronine) and 23 and at the end of the study.
Hematology: hematocrit; hemoglobin concentration; erythrocyte, reticulocyte, and platelet counts; mean cell volume; mean cell hemoglobin; mean cell hemoglobin concentration; and leukocyte count and differentials
Clinical chemistry: urea nitrogen, creatinine, glucose, total protein, albumin, cholesterol, alanine aminotransferase, alkaline phosphatase, creatine kinase, sorbitol dehydrogenase, and bile acids
Thyroid hormones: total triiodothyronine, thyroid stimulating hormone, and total thyroxine
Liver Protein and Enzyme Levels
Liver samples were collected from special study rats on day 23 and from core study rats and mice at study termination for determination of microsomal protein concentration and acetanilide-4-hydroxylase, 7-ethoxyresorufin-O-deethylase, 7-pentoxyresorufin-O-dealkylase, and uridine diphosphate-glucuronosyltransferase activities.
Histopathology
Complete histopathology was performed on core study rats in the 0 and 1,000 mg/kg groups, mice in the 0 and 2,000 mg/kg groups, and all animals that died early. In addition to gross lesions and tissue masses, the following tissues were examined: adrenal gland, bone with marrow, brain, clitoral gland, esophagus, eye, gallbladder (mice), Harderian gland, heart and aorta, large intestine (cecum, colon, rectum), small intestine (duodenum, jejunum, ileum), kidney, liver, lung (with mainstem bronchus), lymph nodes (mandibular and mesenteric), mammary gland, nose, ovary, pancreas, parathyroid gland, pituitary gland, preputial gland, prostate gland, salivary gland, seminal vesicle, skin, spleen, stomach (forestomach and glandular), testis (with epididymis), thymus, thyroid gland, trachea, urinary bladder, and uterus. The liver, lung, and mesenteric lymph nodes were also examined in the remaining dosed groups of rats. Special microscopic reviews were performed on respiratory system tissues of rats and mice.
Sperm Motility and Vaginal Cytology
At the end of the studies, sperm samples were collected from male rats in the 0, 250, 500, and 1,000 mg/kg groups and male mice in the 0, 500, 1,000, and 2,000 mg/kg groups. The following parameters were evaluated: spermatid heads per gram testis and per testis, sperm motility, and sperm per gram cauda epididymis and per cauda epididymis. The left cauda, left epididymis, and left testis were weighed. Vaginal samples were collected for up to 12 consecutive days prior to the end of the studies from female rats in the 0, 250, 500, and 1,000 mg/kg groups and female mice in the 0, 500, 1,000, and 2,000 mg/kg groups.

Hematology, clinical chemistry, and thyroid hormone analyses were performed on special study rats on days 4 (except hematology) and 23 and on core study rats at study termination. Hematology analyses were performed on mice at study termination. Blood was collected from the retroorbital plexus of rats and the retroorbital venous sinus of mice for hematology analyses, and from the retroorbital plexus of special study rats and the heart of core study rats for clinical chemistry and thyroid hormone analyses. Samples were collected into tubes containing EDTA for hematology or serum separator tubes for clinical chemistry and thyroid hormone determinations. Hematology parameters were determined using an Advia 120 analyzer (Bayer Diagnostic Division, Tarrytown, NY). Clinical chemistry parameters and total thyroxine were determined using a Hitachi 911 analyzer (Roche Diagnostics Corporation, Indianapolis, IN). Total triiodothyronine and thyroid stimulating hormone were determined by radioimmunoassay using a commercial kit. The parameters measured are listed in Table 1.

At the end of the 3-month studies, samples were collected for sperm motility or vaginal cytology evaluations on rats in the 0, 250, 500, and 1,000 mg/kg groups and mice in the 0, 500, 1,000, and 2,000 mg/kg groups. The parameters evaluated are listed in Table 1. For 12 consecutive days prior to scheduled terminal euthanasia, the vaginal vaults of the females were moistened with saline, if necessary, and samples of vaginal fluid and cells were stained. Relative numbers of leukocytes, nucleated epithelial cells, and large squamous epithelial cells were determined and used to ascertain estrous cycle stage (i.e., diestrus, proestrus, estrus, and metestrus). Male animals were evaluated for sperm count and motility. The left testis and left epididymis were isolated and weighed. The tail of the epididymis (cauda epididymis) was then removed from the epididymal body (corpus epididymis) and weighed. Test yolk (rats) or modified Tyrone’s buffer (mice) was applied to slides and a small incision was made at the distal border of the cauda epididymis. The sperm effluxing from the incision were dispersed in the buffer on the slides, and the numbers of motile and nonmotile spermatozoa were counted for five fields per slide by two observers. Following completion of sperm motility estimates, each left cauda epididymis was placed in buffered saline solution. Caudae were finely minced, and the tissue was incubated in the saline solution and then heat fixed at 65°C. Sperm density was then determined microscopically with the aid of a hemacytometer. To quantify spermatogenesis, the testicular spermatid head count was determined by removing the tunica albuginea and homogenizing the left testis in phosphate-buffered saline containing 10% dimethyl sulfoxide. Homogenization-resistant spermatid nuclei were counted with a hemacytometer.

Liver samples were collected from special study rats on day 23 and from all core study rats and mice at the end of the studies for cytochrome P450 and uridine diphosphate-glucuronosyltransferase (UDP-GT) activity determinations. Microsomal suspensions were prepared as described by Battelle.^16,17^ The concentration of protein in each suspension was determined using a BCA Protein Assay Kit (Pierce Chemical Co., Rockford, IL). 7-Ethoxyresorufin-O-deethylase (CYP1A1) and 7-pentoxyresorufin-O-dealkylase (CYP2B1) activities were determined spectrofluorimetrically,^18^ acetanilide-4-hydroxylase (CYP1A2) activity was determined by HPLC with ultraviolet detection,^19-21^ and UDP-GT activity toward T_4_ was determined by quantifying the amount of ^125^I-T_4_-glucuronide produced.^22^

Necropsies were performed on all core study rats and mice. The heart, right kidney, liver, lung, spleen, right testis, and thymus were weighed. Tissues for microscopic examination were fixed and preserved in 10% neutral buffered formalin (eyes were first fixed in Davidson’s solution); testes, vaginal tunics of testes, and epididymides were first fixed in modified Davidson’s solution), processed and trimmed, embedded in paraffin, sectioned to a thickness of 4 to 6 µm, and stained with hematoxylin and eosin (H&E). Complete histopathologic examinations were performed by the study laboratory pathologist on 0 and 1,000 mg/kg rats and 0 and 2,000 mg/kg mice. In addition, the liver, lung, and mesenteric lymph node were examined in the remaining dosed groups of rats because lesions in these tissues were identified in the high dose groups. When present, gross lesions were examined in all dosed groups. Table 1 lists the tissues and organs routinely examined.

After a review of the laboratory reports and selected histopathology slides by a quality assessment (QA) pathologist, the findings and reviewed slides were submitted to a NTP Pathology Peer Review (PPR) coordinator for a second independent review. Any inconsistencies in the diagnoses made by the study laboratory and QA pathologists were resolved by the NTP pathology peer review process. Final diagnoses for reviewed lesions represent a consensus of the PPR or a consensus between the study laboratory pathologist, NTP pathologist, QA pathologist(s) and the PPR coordinator. Details of these review procedures have been described, in part, by Maronpot and Boorman^23^ and Boorman et al.^24^

To determine the nature of the pulmonary granulomatous and chronic active inflammatory lesions, special microscopic reviews (Reviews 1 through 5) were performed on respiratory system tissues of rats and mice in the current 3-month corn oil gavage study of tetrabromobisphenol A-bis(2,3-dibromopropyl ether), on lung tissue of rats from the 3-month interim evaluation in the 2-year corn oil gavage study of tetrabromobisphenol A,^25^ and on lung tissue of rats from the 3-month feed study of p-toluenesulfonamide.^26^ For Review 1, H&E stained sections of the nasal cavity, larynx, and trachea from all vehicle control and treated F344/NTac rats in the current study were examined to determine if gavage-related reflux may have caused granulomatous lesions in the lung. For Review 2, Sudan black stained sections of the lung from three vehicle control and three treated F344/NTac rats in the current study were examined to determine if corn oil droplets were present and whether their presence correlated with the occurrence of granulomatous inflammation. For Review 3, H&E and Sudan black stained sections of the lung of five vehicle control and five high dose Wistar Han rats at the 3-month interim evaluation in the 2-year corn oil gavage study of tetrabromobisphenol A^25^ were evaluated for the presence of granulomatous inflammation and corn oil droplets. For Review 4, H&E and Sudan black stained sections of the lung of five control and five high dose F344/NTac rats from the 3-month feed study of p-toluenesulfonamide were evaluated for the presence of granulomatous inflammation and corn oil droplets. For Review 5, Sudan black stained sections of the lung from three vehicle control and three high dose B6C3F1/N mice in the current study were examined to determine if corn oil droplets were present and whether their presence correlated with the occurrence of granulomatous lesions.

## Statistical Methods

### Calculation and Analysis of Lesion Incidences

The incidences of lesions are presented in Appendix A as the numbers of animals bearing such lesions at a specific anatomic site and the numbers of animals with that site examined microscopically. The Fisher exact test,^27^ a procedure based on the overall proportion of affected animals, was used to determine significance.

### Analysis of Continuous Variables

Two approaches were employed to assess the significance of pairwise comparisons between dosed and vehicle control groups in the analysis of continuous variables. Organ and body weight data, which historically have approximately normal distributions, were analyzed with the parametric multiple comparison procedures of Dunnett^28^ and Williams.^29,30^ Hematology, clinical chemistry, thyroid hormone, microsomal protein, cytochrome P450, UDP-GT, spermatid, and epididymal spermatozoal data, which have typically skewed distributions, were analyzed using the nonparametric multiple comparison methods of Shirley^31^ (as modified by Williams^32^) and Dunn.^33^ Jonckheere’s test^34^ was used to assess the significance of the dose-related trends and to determine whether a trend-sensitive test (Williams’ or Shirley’s test) was more appropriate for pairwise comparisons than a test that does not assume a monotonic dose-related trend (Dunnett’s or Dunn’s test). Prior to statistical analysis, extreme values identified by the outlier test of Dixon and Massey^35^ were examined by NTP personnel, and implausible values were eliminated from the analysis. Proportions of regular cycling females in each dosed group were compared to the vehicle control group using the Fisher exact test.^27^ Tests for extended periods of estrus, diestrus, metestrus, and proestrus, as well as skipped estrus and skipped diestrus, were constructed based on a Markov chain model proposed by Girard and Sager.^36^ For each dose group, a transition probability matrix was estimated for transitions among the proestrus, estrus, metestrus, and diestrus stages, with provision for extended stays within each stage as well as for skipping estrus or diestrus within a cycle. Equality of transition matrices among dose groups and between the vehicle control group and each dosed group was tested using chi-square statistics.

## Quality Assurance Methods

The 3-month studies were conducted in compliance with Food and Drug Administration Good Laboratory Practice Regulations.^37^ In addition, as records from the 3-month studies were submitted to the NTP Archives, these studies were audited retrospectively by an independent quality assessment contractor. Separate audits covered completeness and accuracy of the pathology data, pathology specimens, final pathology tables, and a draft of this NTP Toxicity Study Report. Audit procedures and findings are presented in the reports and are on file at NIEHS. The audit findings were reviewed and assessed by NTP staff, and all comments were resolved or otherwise addressed during the preparation of this Toxicity Study Report.

## Genetic Toxicology

### Salmonella typhimurium Mutagenicity Test Protocol

Tetrabromobisphenol A-bis(2,3-dibromopropyl ether) (lot 324811, Great Lakes Chemical Corp.) was tested for mutagenicity in three strains of Salmonella typhimurium following protocols reported by Zeiger et al.^38^ Tetrabromobisphenol A-bis(2,3-dibromopropyl ether) was sent to the testing laboratory as a coded sample. It was incubated with the S. typhimurium tester strains TA98, TA100, and TA102 either in buffer or S9 mix (metabolic activation enzymes and cofactors from Aroclor 1254-induced male Sprague Dawley rat liver) for 20 minutes at 37º C. Top agar supplemented with L-histidine and d-biotin was added, and the contents of the tubes were mixed and poured onto the surfaces of minimal glucose agar plates. Histidine-independent mutant colonies arising on these plates were counted following incubation for 2 days at 37º C.

Each trial consisted of triplicate plates of concurrent positive and negative controls and of five doses of tetrabromobisphenol A-bis(2,3-dibromopropyl ether). In the absence of toxicity, the highest concentration tested was 10,000 µg/plate.

In this assay, a positive response is defined as a reproducible, dose-related increase in histidine-independent (revertant) colonies in any one strain/activation combination. An equivocal response is defined as an increase in revertants that is not dose related, is not reproducible, or is not of sufficient magnitude to support a determination of mutagenicity. A negative response is obtained when no increase in revertant colonies is observed following chemical treatment. There is no minimum percentage or fold increase required for a chemical to be judged positive or weakly positive although positive calls are typically reserved for increases in mutant colonies that are at least twofold over background.

### Mouse Peripheral Blood Micronucleus Test Protocol

A detailed discussion of this assay is presented by MacGregor et al.^39^ At the termination of the 3-month toxicity study, peripheral blood samples were obtained from male and female mice. Smears were immediately prepared and fixed in absolute methanol. The methanol-fixed slides were stained with acridine orange and coded. Slides were scanned to determine the frequency of micronucleated cells in 2,000 normochromatic erythrocytes (NCEs) in each of five animals per dose group. In addition, the percentage of polychromatic erythrocytes in a population of 1,000 erythrocytes was determined as a measure of bone marrow toxicity.

The results were tabulated as the mean of the pooled results from all animals within a treatment group, plus or minus the standard error of the mean. The frequency of micronucleated cells among NCEs was analyzed by a statistical software package that tested for increasing trend over dose groups using a one-tailed Cochran-Armitage trend test, followed by pairwise comparisons between each dosed group and the vehicle control group. In the presence of excess binomial variation, as detected by a binomial dispersion test, the binomial variance of the Cochran-Armitage test was adjusted upward in proportion to the excess variation. In the micronucleus test, an individual trial is considered positive if the trend test P value is less than or equal to 0.025 or if the P value for any single dosed group is less than or equal to 0.025 divided by the number of dosed groups. After the statistical analysis of the test data has been completed, the scientific staff determines the final call for the assay, considering the results of statistical analyses, the reproducibility of any effects observed, and the magnitudes of those effects.

### Evaluation Protocol

These are the basic guidelines for arriving at an overall assay result for assays performed by the National Toxicology Program. Statistical as well as biological factors are considered. For an individual assay, the statistical procedures for data analysis have been described in the preceding protocols. There have been instances, however, in which multiple samples of a chemical were tested in the same assay, and different results were obtained among these samples and/or among laboratories. Results from more than one aliquot or from more than one laboratory are not simply combined into an overall result. Rather, all the data are critically evaluated, particularly with regard to pertinent protocol variations, in determining the weight of evidence for an overall conclusion of chemical activity in an assay. In addition to multiple aliquots, the in vitro assays have another variable that must be considered in arriving at an overall test result. In vitro assays are conducted with and without exogenous metabolic activation. Results obtained in the absence of activation are not combined with results obtained in the presence of activation; each testing condition is evaluated separately. The results presented in the Abstract of this Toxicity Study Report represent a scientific judgment of the overall evidence for activity of the chemical in an assay.