# Appendix I Sentinel Animal Program

## I.1 Methods

Rodents used in the National Toxicology Program are produced in optimally clean facilities to eliminate potential pathogens that may affect study results. The Sentinel Animal Program is part of the periodic monitoring of animal health that occurs during the toxicological evaluation of compounds. Under this program, the disease state of the rodents is monitored via sera or feces from extra (sentinel) animals in the study rooms. The sentinel animals and the study animals are subject to identical environmental conditions. The sentinel animals come from the same production source and weanling groups as the animals used for the studies of test compounds.

Blood samples were collected, allowed to clot, and the serum was separated. All samples were processed appropriately and tested at BioReliance Corporation (Rockville, MD) for determination of the presence of pathogens. The laboratory methods and agents for which testing was performed are tabulated below; the times at which samples were collected during the studies are also listed.

Blood samples were collected from five male and five female rats and mice at each time point.

Table I-1 Laboratory Methods and Agents Tested for in the Sentinel Animal Program

Method and Test | Time of Collection
Rats
ELISA
PVM (pneumonia virus of mice) | End of quarantine, 4 weeks, study termination
RCV/SDA (rat coronavirus/sialodacryoadenitis virus) | End of quarantine, 4 weeks, study termination
Sendai | End of quarantine, 4 weeks, study termination
Immunofluorescence Assay
Parvovirus | End of quarantine, 4 weeks, study termination
RCV/SDA | End of quarantine, study termination
Mice
ELISA
Ectromelia virus | End of quarantine, 4 weeks, study termination
EDIM (epizootic diarrhea of infant mice) | End of quarantine, 4 weeks, study termination
GDVII (mouse encephalomyelitis virus) | End of quarantine, 4 weeks, study termination
LCM (lymphocytic choriomeningitis virus) | End of quarantine, 4 weeks, study termination
Mouse adenoma virus-1 | End of quarantine, 4 weeks, study termination
MHV (mouse hepatitis virus) | End of quarantine, 4 weeks, study termination
MMV VP2 (mouse minute virus viral protein 2) | End of quarantine, 4 weeks, study termination
MPV VP2 (mouse parvovirus viral protein 2) | End of quarantine, 4 weeks, study termination
PVM | End of quarantine, 4 weeks, study termination
Reovirus 3 | End of quarantine, 4 weeks, study termination
Sendai | End of quarantine, 4 weeks, study termination

## I.2 Results

All test results were negative.