# Appendix G Chemical Characterization and Dose Formulation Studies

## G.1 Procurement and Characterization

### G.1.1 Tetrabromobisphenol A-bis(2,3-dibromopropyl ether)

Tetrabromobisphenol A-bis(2,3-dibromopropyl ether) was obtained from Great Lakes Chemical Corporation (West Lafayette, IN) in one lot (534106) that was used during the 3-month studies. Identity and purity analyses were conducted by the analytical chemistry laboratory at Midwest Research Institute (Kansas City, MO). The study laboratory at Battelle Columbus Operations (Columbus, OH) conducted additional identity analyses and confirmed purity. Reports on analyses performed in support of the tetrabromobisphenol A-bis(2,3-dibromopropyl ether) studies are on file at the National Institute of Environmental Health Sciences.

Lot 534106 of the test chemical, a white powder, was identified as tetrabromobisphenol A-bis(2,3-dibromopropyl ether) by the analytical chemistry laboratory using infrared (IR) and proton nuclear magnetic resonance (NMR) spectroscopy. The study laboratory confirmed the identity of the test article using IR spectroscopy. All spectra were consistent with the literature spectra of tetrabromobisphenol A-bis(2,3-dibromopropyl ether).^45,46^ Representative IR and NMR spectra are presented in Figure G-1 and Figure G-2, respectively.

For lot 534106, the analytical chemistry laboratory determined the melting point using differential scanning calorimetry (DSC) and the purity profile using high-performance liquid chromatography (HPLC) with ultraviolet (UV) detection; in addition, the analytical chemistry laboratory determined the tentative identity of a single impurity using liquid chromatography (LC) coupled with mass spectrometry (MS).

DSC was conducted with a Perkin Elmer Diamond Differential Scanning Calorimeter (Perkin Elmer, Waltham, MA), an indium reference, and a heating ramp from 25° to 300°C at 10°C per minute after an initial 1 minute hold. HPLC/UV was conducted using system A, and LC/MS was conducted using system A coupled with an MS detector (Micromass Quattro LC Dual Quadrupole, Waters Corporation, Milford, MA) operated in full scan mode with negative atmospheric pressure chemical ionization.

A) The HPLC system included a liquid chromatograph (Waters Corporation), an Inertsil^®^ ODS-2, 250 mm × 4.6 mm, 5 μm particle size column (Alltech Associates, Inc., Deerfield, IL), an isocratic mobile phase of 90:10 acetonitrile with 0.5% acetic acid:18 mM aqueous ammonium acetate with 0.5% acetic acid, UV detection at 280 nm, and a flow rate of 1 mL/minute.

Melting point analysis by DSC indicated that lot 534106 of the test article contained impurities. Purity profile analysis by HPLC/UV detected 12 reportable impurities with a total relative peak area of approximately 5.8%. One impurity (approximately 2% relative to the total peak area) was tentatively identified as 1,3-dibromo-2-{[(2E)-3-bromoprop-2-en-1-yl]oxy}-5-{1-[3,5-dibromo-4-(2,3-dibromopropoxy)phenyl]-1-methylethyl}benzene by LC/MS. The overall purity of lot 534106 was determined to be approximately 94%.

To ensure stability, the bulk chemical was stored at room temperature (~25°C) in amber glass bottles. Periodic reanalyses of the bulk chemical were performed by the study laboratory during the 3-month studies using HPLC/UV by system A, and no degradation of the test article was detected.

### G.1.2 Corn Oil

Corn oil was obtained in two lots (UU0854 and UW0493) from Spectrum Chemicals and Laboratory Products (Gardena, CA) and was used as the vehicle in the 3-month studies. Periodic analyses of the corn oil vehicle performed by the study laboratory using potentiometric titration demonstrated peroxide concentrations less than the rejection level of 3 mEq/kg.

## G.2 Preparation and Analysis of Dose Formulations

The dose formulations were prepared four times by mixing tetrabromobisphenol A-bis(2,3-dibromopropyl ether) with corn oil to give the required concentrations (Table G-1). The dose formulations were stored in sealed clear glass bottles enclosed in amber plastic bags at room temperature and used within 41 days.

Homogeneity studies of 1.0 and 600 mg/mL formulations, and stability studies of the 1.0 mg/mL formulation were performed by the analytical chemistry laboratory using HPLC/UV by system B; the study laboratory used the same analytical system to perform additional homogeneity studies of 12.5, 25, 50, 400, and 800 mg/mL formulations and a gavageability study of a 200 mg/mL dose formulation.

B) The HPLC system included a liquid chromatograph (Waters Corporation or Agilent Inc., Palo Alto, CA), an Inertsil C_18_, 250 mm × 4.6 mm, 5 μm particle size column (Alltech Associates, Inc.), an isocratic mobile phase of 95:5 acetonitrile:water, with UV detection at 280 nm, and a flow rate of 1.0 mL/minute.

Homogeneity was deemed acceptable for all of the formulations; stability was confirmed for at least 42 days for dose formulations stored in sealed glass containers at temperatures up to 25°C, and for 3 hours under simulated animal room conditions. Gavageability of the 200 mg/mL dose formulation was confirmed by the study laboratory.

Periodic analyses of the dose formulations of tetrabromobisphenol A-bis(2,3-dibromopropyl ether) were conducted by the study laboratory using HPLC/UV by system B. During the 3-month studies, the dose formulations were analyzed three times; 14 of the 15 dose formulations for rats and mice were within 10% of the target concentrations (Table G-2). Animal room samples of these dose formulations were also analyzed; 14 of 18 animal room samples for rats and 12 of 15 for mice were within 10% of the target concentrations.

Table G-1 Preparation and Storage of Dose Formulations in the Three-month Gavage Studies of Tetrabromobisphenol A-bis(2,3-dibromopropyl ether)

Three-month Studies
Preparation
Dose formulations were prepared by adding the appropriate weight of tetrabromobisphenol A-bis(2,3-dibromopropyl ether) directly into an appropriate sized glass beaker, adding enough corn oil to wet the test article, and stirring with a spatula to form a smooth slurry. The spatula and sides of the beaker were rinsed with corn oil, and the beaker contents were diluted to final volume with corn oil and stirred using an overhead stirrer with a vigorous vortex for approximately 15 minutes; during this mixing, the bottom of the beaker was periodically scraped with a spatula to ensure that the test article did not stick to it. Dose formulations were prepared four times.
Chemical Lot Number
534106
Maximum Storage Time
42 days
Storage Conditions
Stored in sealed clear glass bottles in amber plastic bags at 25°C.
Study Laboratory
Battelle Columbus Operations (Columbus, OH)

Table G-2 Results of Analyses of Dose Formulations Administered to Rats and Mice in the Three-month Gavage Studies of Tetrabromobisphenol A-bis(2,3-dibromopropyl ether)

Date Prepared | Date Analyzed | Target Concentration (mg/mL) | Determined Concentration^a^ (mg/mL) | Difference from Target (%)
Rats and Mice
December 28, 2005^b^ | January 4–5, 2006 | 12.5 | 12.23 | −2
| | 50 | 48.29 | −3
| | 100 | 100.3 | 0
| | 200 | 191.4 | −4
January 6, 2006 | January 6, 2006 | 25 | 25.15 | +1
February 20, 2006 | February 22–23, 2006 | 12.5 | 10.89^c^ | −13
| | 25 | 23.48 | −6
| | 50 | 49.61 | −1
| | 100 | 89.98 | −10
| | 200 | 184.8 | −8
March 16, 2006 | March 17–18, 2006 | 12.5 | 12.45 | 0
| | 25 | 24.85 | −1
| | 50 | 46.15 | −8
| | 100 | 94.33 | −6
| | 200 | 197.7 | −1
Animal Room Samples
Rats
December 28, 2005^b^ | February 3–4, 2006 | 12.5 | 11.84 | −5
| | 50 | 45.96 | −8
| | 100 | 91.16 | −9
| | 200 | 194.9 | −3
January 6, 2006 | January 6, 2006 | 25 | 24.63 | −1
February 20, 2006 | March 29–30, 2006 | 12.5 | 11.92 | −5
| | 25 | 24.16 | −3
| | 50 | 47.96 | −4
| | 100 | 91.77 | −8
| | 200 | 182.8 | −9
March 16, 2006 | April 18–19, 2006 | 12.5 | 14.14 | +13
| | 25 | 25.97 | +4
| | 50 | 78.64^d^ | +57
| | 50 | 44.56^e^ | −11
| | 100 | 92.49 | −8
| | 200 | 186.7 | −7
| May 12, 2006 | 12.5 | 11.82^f^ | −5
| | 50 | 43.85^f^ | −12
Mice
December 28, 2005^b^ | February 3–4, 2006 | 12.5 | 13.01 | +4
| | 50 | 50.53 | +1
| | 100 | 91.09 | −9
| | 200 | 193.6 | −3
January 6, 2006 | January 6, 2006 | 25 | 25.09 | 0
February 20, 2006 | March 29–30, 2006 | 12.5 | 12.09 | −3
| | 25 | 23.95 | −4
| | 50 | 48.26 | −3
| | 100 | 94.36 | −6
| | 200 | 183.7 | −8
March 16, 2006 | April 18–19, 2006 | 12.5 | 14.87 | +19
| | 25 | 30.33 | +21
| | 50 | 56.26 | +13
| | 100 | 92.34 | −8
| | 200 | 183.6 | −8

^a^ Results of duplicate analyses. For rats, dosing volume = 5 mL/kg; 12.5 mg/mL = 62.5 mg/kg, 25 mg/mL = 125 mg/kg, 50 mg/mL = 250 mg/kg, 100 mg/mL = 500 mg/kg, 200 mg/mL = 1,000 mg/kg. For mice, dosing volume = 10 mL/kg; 12.5 mg/mL = 125 mg/kg, 25 mg/mL = 250 mg/kg, 50 mg/mL = 500 mg/kg, 100 mg/mL = 1,000 mg/kg, 200 mg/mL = 2,000 mg/kg.

^b^ The 25 mg/mL formulation prepared on December 28, 2005, was replaced by one prepared on January 6, 2006, due to a preparation error.

^c^ Formulation was outside the acceptable range of ± 10% of target concentration, but used at NTP’s direction.

^d^ Results indicated that this formulation was not adequately resuspended prior to sampling.

^e^ Two additional replicates were prepared from the same 50 mg/mL formulation, analyzed, and had peak responses that were closer to meeting the acceptance criterion.

^f^ Because sufficient volume of this dose formulation remained, NTP directed that it be resampled and reanalyzed.

Figure G-1

Infrared Absorption Spectrum of Tetrabromobisphenol A-bis(2,3-dibromopropyl ether)

Figure G-2

Proton Nuclear Magnetic Resonance Spectrum of Tetrabromobisphenol A-bis(2,3-dibromopropyl ether)