# Appendix F Microsomal Protein Concentration and Liver Enzyme Activity Data

Table F-1 Microsomal Protein Concentration and Liver Enzyme Activities for Rats in the Three-month Gavage Study of Tetrabromobisphenol A-bis(2,3-dibromopropyl ether)^a^

| Vehicle Control | 62.5 mg/kg | 125 mg/kg | 250 mg/kg | 500 mg/kg | 1,000 mg/kg
Male
n
Day 23 | 10 | 10 | 10 | 10 | 10 | 9
Week 14 | 10 | 8 | 10 | 10 | 10 | 10
Microsomal protein (mg/mL)
Day 23 | 10.54 ± 0.31 | 11.70 ± 0.64 | 17.17 ± 0.77** | 18.26 ± 0.54** | 17.35 ± 0.22** | 18.28 ± 0.52**
Week 14 | 12.89 ± 0.65 | 13.47 ± 1.05 | 15.61 ± 1.13* | 17.91 ± 1.26** | 17.31 ± 0.71** | 17.73 ± 0.94**
Acetanilide-4-hydroxylase (A4H) (nmol/minute per mg microsomal protein)
Day 23 | 0.914 ± 0.038 | 0.852 ± 0.040 | 0.579 ± 0.049** | 0.534 ± 0.020** | 0.504 ± 0.024** | 0.479 ± 0.029**
Week 14 | 0.762 ± 0.062 | 0.735 ± 0.030 | 0.629 ± 0.038 | 0.513 ± 0.014** | 0.567 ± 0.027** | 0.526 ± 0.018**
7-Ethoxyresorufin-O-deethylase (EROD) (pmol/minute per mg microsomal protein)
Day 23 | 60.1 ± 2.2 | 55.6 ± 2.9 | 37.4 ± 2.9** | 39.5 ± 1.5** | 38.2 ± 2.3** | 35.1 ± 1.9**
Week 14 | 48.2 ± 1.9 | 47.7 ± 2.0 | 39.1 ± 2.6* | 35.4 ± 1.6** | 39.2 ± 1.4** | 34.7 ± 0.9**
7-Pentoxyresorufin-O-dealkylase (PROD) (pmol/minute per mg microsomal protein)
Day 23 | 8.4 ± 0.2 | 7.7 ± 0.3 | 5.7 ± 0.3** | 5.5 ± 0.2** | 5.7 ± 0.4** | 4.9 ± 0.3**
Week 14 | 8.8 ± 0.3 | 8.9 ± 0.6 | 7.0 ± 0.3** | 6.6 ± 0.3** | 7.2 ± 0.4** | 6.3 ± 0.1**
UDP-Glucuronosyltransferase (UDP-GT) (pmol/minute per mg microsomal protein)
Day 23 | 3.24 ± 0.14 | 3.11 ± 0.12 | 2.55 ± 0.15** | 2.51 ± 0.13** | 2.48 ± 0.12** | 2.47 ± 0.11**
Week 14 | 4.29 ± 0.23 | 3.81 ± 0.17 | 3.68 ± 0.19 | 3.46 ± 0.19* | 3.71 ± 0.21* | 3.47 ± 0.15**
Female
n
Day 23 | 10 | 10 | 10 | 10 | 10 | 10
Week 14 | 9 | 10 | 10 | 10 | 10 | 10
Microsomal protein (mg/mL)
Day 23 | 10.32 ± 0.28 | 10.58 ± 0.21 | 16.84 ± 0.84** | 17.74 ± 0.43** | 18.01 ± 0.20** | 18.60 ± 0.41**
Week 14 | 14.88 ± 1.03 | 15.37 ± 0.67 | 17.79 ± 0.85* | 18.96 ± 0.75** | 18.69 ± 0.59** | 19.46 ± 0.63**
Acetanilide-4-hydroxylase (A4H) (nmol/minute per mg microsomal protein)
Day 23 | 0.787 ± 0.041 | 0.739 ± 0.033 | 0.399 ± 0.049** | 0.371 ± 0.024** | 0.361 ± 0.015** | 0.336 ± 0.010**
Week 14 | 0.763 ± 0.055 | 0.716 ± 0.035 | 0.613 ± 0.025* | 0.581 ± 0.032** | 0.595 ± 0.022** | 0.586 ± 0.039**
7-Ethoxyresorufin-O-deethylase (EROD) (pmol/minute per mg microsomal protein)
Day 23 | 59.0 ± 2.0 | 57.8 ± 1.4 | 34.1 ± 2.3** | 34.9 ± 2.3** | 32.4 ± 2.0** | 30.7 ± 2.8**
Week 14 | 63.2 ± 2.1 | 58.9 ± 2.3 | 52.3 ± 2.6** | 48.6 ± 1.8** | 51.3 ± 0.9** | 47.8 ± 2.1**
7-Pentoxyresorufin-O-dealkylase (PROD) (pmol/minute per mg microsomal protein)
Day 23 | 6.1 ± 0.3 | 5.6 ± 0.3 | 3.2 ± 0.3** | 3.7 ± 0.2** | 3.3 ± 0.2** | 3.0 ± 0.2**
Week 14 | 6.4 ± 0.2 | 6.3 ± 0.3 | 4.8 ± 0.3** | 5.1 ± 0.2** | 5.5 ± 0.3** | 5.2 ± 0.2**
UDP-Glucuronosyltransferase (UDP-GT) (pmol/minute per mg microsomal protein)
Day 23 | 3.25 ± 0.16 | 3.25 ± 0.13 | 2.50 ± 0.21** | 2.72 ± 0.14* | 2.66 ± 0.20* | 2.73 ± 0.19*
Week 14 | 4.48 ± 0.16 | 4.72 ± 0.13 | 4.44 ± 0.21 | 4.11 ± 0.11 | 4.23 ± 0.18 | 4.18 ± 0.13

* Significantly different (P ≤ 0.05) from the vehicle control group by Shirley’s test.

** P ≤ 0.01.

^a^ Data are given as mean ± standard error. Statistical tests are performed on unrounded data.

Table F-2 Microsomal Protein Concentration and Liver Enzyme Activities for Mice in the Three-month Gavage Study of Tetrabromobisphenol A-bis(2,3-dibromopropyl ether)^a^

| Vehicle Control | 125 mg/kg | 250 mg/kg | 500 mg/kg | 1,000 mg/kg | 2,000 mg/kg
Male
n | 10 | 10 | 10 | 10 | 10 | 10
Microsomal protein (mg/mL)
Week 14 | 11.65 ± 0.98 | 13.93 ± 0.92 | 18.10 ± 0.93** | 21.98 ± 1.46** | 20.21 ± 1.05** | 21.35 ± 1.00**
Acetanilide-4-hydroxylase (A4H) (nmol/minute per mg microsomal protein)
Week 14 | 0.961 ± 0.062 | 0.838 ± 0.076 | 0.601 ± 0.044** | 0.558 ± 0.033** | 0.514 ± 0.033** | 0.532 ± 0.030**
7-Ethoxyresorufin-O-deethylase (EROD) (pmol/minute per mg microsomal protein)
Week 14 | 183.1 ± 6.2 | 167.7 ± 9.8 | 132.0 ± 8.6** | 116.3 ± 4.5** | 103.8 ± 5.4** | 108.5 ± 3.8**
7-Pentoxyresorufin-O-dealkylase (PROD) (pmol/minute per mg microsomal protein)
Week 14 | 8.7 ± 0.3 | 7.1 ± 0.4** | 5.4 ± 0.2** | 5.2 ± 0.2** | 4.5 ± 0.2** | 4.1 ± 0.2**
UDP-Glucuronosyltransferase (UDP-GT) (pmol/minute per mg microsomal protein)
Week 14 | 2.14 ± 0.09 | 2.08 ± 0.16 | 1.96 ± 0.13 | 1.88 ± 0.13 | 1.77 ± 0.11 | 1.85 ± 0.12
Female
n | 10 | 10 | 10 | 10 | 9 | 10
Microsomal protein (mg/mL)
Week 14 | 12.42 ± 0.50 | 14.91 ± 1.93 | 18.37 ± 1.16** | 21.02 ± 0.67** | 23.74 ± 1.63** | 22.52 ± 1.12**
Acetanilide-4-hydroxylase (A4H) (nmol/minute per mg microsomal protein)
Week 14 | 0.657 ± 0.047 | 0.544 ± 0.041 | 0.378 ± 0.027** | 0.393 ± 0.015** | 0.389 ± 0.028** | 0.331 ± 0.015**
7-Ethoxyresorufin-O-deethylase (EROD) (pmol/minute per mg microsomal protein)
Week 14 | 149.8 ± 9.7 | 129.0 ± 10.8 | 93.8 ± 5.4** | 110.4 ± 4.7** | 98.5 ± 6.2** | 89.4 ± 3.3**
7-Pentoxyresorufin-O-dealkylase (PROD) (pmol/minute per mg microsomal protein)
Week 14 | 14.5 ± 0.9 | 12.0 ± 1.1 | 8.8 ± 0.6** | 9.2 ± 0.4** | 8.8 ± 0.5** | 7.8 ± 0.3**
UDP-Glucuronosyltransferase (UDP-GT) (pmol/minute per mg microsomal protein)
Week 14 | 3.54 ± 0.23 | 3.20 ± 0.19 | 2.42 ± 0.18** | 2.49 ± 0.17** | 2.44 ± 0.17** | 2.38 ± 0.13**

** Significantly different (P ≤ 0.01) from the vehicle control group by Shirley’s test.

^a^ Data are given as mean ± standard error. Statistical tests are performed on unrounded data.