# Appendix E Genetic Toxicology

Table E-1 Mutagenicity of Tetrabromobisphenol A-bis(2,3-dibromopropyl ether) in Salmonella typhimurium^a^

Strain | Dose (μg/plate) | Without S9 | With 10% Rat S9
TA102 | 0 | 332 ± 24 | 397 ± 20
| 100 | 357 ± 22 | 380 ± 12
| 333 | 302 ± 19 | 399 ± 2
| 1,000 | 302 ± 6 | 345 ± 8
| 3,333 | 264 ± 10^b^ | 343 ± 14^b^
| 10,000 | 304 ± 9^b^ | 391 ± 12^b^
Trial summary | | Negative | Negative
Positive control^c^ | | 999 ± 16 | 1,626 ± 24
TA100 | 0 | 146 ± 8 | 138 ± 6
| 100 | 146 ± 11 | 137 ± 6
| 333 | 145 ± 6 | 100 ± 11
| 1,000 | 160 ± 8^b^ | 131 ± 9^b^
| 3,333 | 193 ± 14^d^ | 158 ± 7^d^
| 10,000 | 186 ± 4^d^ | 145 ± 8^d^
Trial summary | | Negative | Negative
Positive control | | 534 ± 33 | 759 ± 27
TA98 | 0 | 14 ± 2 | 23 ± 0
| 100 | 14 ± 0 | 22 ± 3
| 333 | 14 ± 2 | 23 ± 1
| 1,000 | 16 ± 2^b^ | 29 ± 1^b^
| 3,333 | 15 ± 3^d^ | 23 ± 4^d^
| 10,000 | 15 ± 1^d^ | 23 ± 5^d^
Trial summary | | Negative | Negative
Positive control | | 78 ± 7 | 488 ± 34

^a^ Study was performed at BioReliance Corporation. Data are presented as revertants/plate (mean ± standard error) from three plates. The detailed protocol is presented by Zeiger et al.^38^ Dimethylsulfoxide was the solvent control.

^b^ Precipitate on plate.

^c^ The positive controls in the absence of metabolic activation were sodium azide (TA100), cumene hydroperoxide (TA102), and 4-nitro-o-phenylenediamine (TA98). The positive controls for metabolic activation were 2-aminoanthracene (TA98 and TA100) or sterigmatocystin (TA102).

^d^ Slight toxicity and precipitate on plate.

Table E-2 Frequency of Micronuclei in Peripheral Blood Erythrocytes of Mice Following Administration of Tetrabromobisphenol A-bis(2,3-dibromopropyl ether) by Gavage for Three Months^a^

| Dose (mg/kg) | Number of Mice with Erythrocytes Scored | Micronucleated NCEs/1,000 NCEs^b^ | P Value^c^ | PCEs^b^ (%)
Male
Corn oil^d^ | 0 | 5 | 2.20 ± 0.41 | | 2.90 ± 0.21
Tetrabromobisphenol A-bis(2,3-dibromopropyl ether)
| 125 | 5 | 2.00 ± 0.42 | 0.6213 | 3.10 ± 0.22
| 250 | 5 | 2.20 ± 0.41 | 0.5000 | 3.24 ± 0.13
| 500 | 5 | 2.20 ± 0.20 | 0.5000 | 3.52 ± 0.38
| 1,000 | 5 | 2.40 ± 0.37 | 0.3839 | 3.04 ± 0.18
| 2,000 | 5 | 2.20 ± 0.12 | 0.5000 | 2.72 ± 0.18
| | | P = 0.412^e^
Female
Corn oil | 0 | 5 | 1.40 ± 0.24 | | 3.40 ± 0.20
Tetrabromobisphenol A-bis(2,3-dibromopropyl ether)
| 125 | 5 | 1.50 ± 0.16 | 0.4263 | 3.40 ± 0.06
| 250 | 5 | 1.30 ± 0.30 | 0.5764 | 3.74 ± 0.16
| 500 | 5 | 1.40 ± 0.37 | 0.5000 | 2.94 ± 0.41
| 1,000 | 5 | 2.40 ± 0.37 | 0.0522 | 3.32 ± 0.23
| 2,000 | 5 | 1.90 ± 0.33 | 0.1918 | 3.28 ± 0.18
| | | P = 0.068

^a^ Study was performed at ILS, Inc. The detailed protocol is presented by MacGregor et al.^39^ NCE = normochromatic erythrocyte; PCE = polychromatic erythrocyte.

^b^ Mean ± standard error.

^c^ Pairwise comparison with the vehicle control group; dosed group values are significant at P ≤ 0.005.

^d^ Vehicle control.

^e^ Significance of micronucleated NCEs/1,000 NCEs tested by the one-tailed Cochran-Armitage trend test; significant at P ≤ 0.025.