# Appendix D Reproductive Tissue Evaluations and Estrous Cycle Characterization

Table D-1 Summary of Reproductive Tissue Evaluations for Male Rats in the Three-month Gavage Study of Tetrabromobisphenol A-bis(2,3-dibromopropyl ether)^a^

| Vehicle Control | 250 mg/kg | 500 mg/kg | 1,000 mg/kg
n | 10 | 10 | 10 | 10
Weights (g)
Necropsy body wt | 330 ± 9 | 342 ± 6 | 333 ± 5 | 320 ± 8
L. Cauda epididymis | 0.1323 ± 0.0044 | 0.1429 ± 0.0031 | 0.1320 ± 0.0026 | 0.1322 ± 0.0055
L. Epididymis | 0.3898 ± 0.0077 | 0.4125 ± 0.0068 | 0.3925 ± 0.0064 | 0.3843 ± 0.0103
L. Testis | 1.4025 ± 0.0276 | 1.4796 ± 0.0229 | 1.4196 ± 0.0222 | 1.3703 ± 0.0500
Spermatid measurements
Spermatid heads (10^6^/g testis) | 164.1 ± 8.2 | 175.1 ± 5.9 | 175.1 ± 4.5 | 166.6 ± 3.3
Spermatid heads (10^6^/testis) | 192.4 ± 9.3 | 215.5 ± 5.9 | 209.5 ± 4.8 | 189.9 ± 6.3
Epididymal spermatozoal measurements
Sperm motility (%) | 86 ± 0 | 84 ± 1 | 84 ± 0 | 85 ± 1
Sperm (10^6^/g cauda epididymis) | 809.7 ± 34.3 | 738.6 ± 49.4 | 721.1 ± 47.6 | 732.8 ± 51.2
Sperm (10^6^/cauda epididymis) | 107.4 ± 6.3 | 105.8 ± 7.8 | 94.7 ± 5.4 | 95.8 ± 5.7

^a^ Data are presented as mean ± standard error. Differences from the vehicle control group are not significant by Dunnett’s test (body and tissue weights) or Dunn’s test (spermatid and epididymal spermatozoal measurements).

Table D-2 Estrous Cycle Characterization for Female Rats in the Three-month Gavage Study of Tetrabromobisphenol A-bis(2,3-dibromopropyl ether)^a^

| Vehicle Control | 250 mg/kg | 500 mg/kg | 1,000 mg/kg
Number weighed at necropsy | 9 | 10 | 10 | 10
Necropsy body wt (g) | 191 ± 4 | 194 ± 4 | 188 ± 3 | 190 ± 4
Proportion of regular cycling females^b^ | 9/9 | 10/10 | 10/10 | 10/10
Estrous cycle length (days) | 4.9 ± 0.06 | 4.8 ± 0.13 | 4.9 ± 0.07 | 4.9 ± 0.08
Estrous stages (% of cycle)
Diestrus | 50.0 | 60.8 | 60.8 | 56.7
Proestrus | 18.3 | 15.0 | 18.3 | 16.7
Estrus | 20.8 | 22.5 | 20.8 | 25.0
Metestrus | 0.8 | 1.7 | 0.0 | 1.7

^a^ Necropsy body weights and estrous cycle length data are presented as mean ± standard error. Differences from the vehicle control group are not significant by Dunnett’s test (body weights) or Dunn’s test (estrous cycle length). Tests for equality of transition probability matrices among all groups and between the vehicle control group and each dosed group indicated dosed females did not have extended estrus or diestrus.

^b^ Number of females with a regular cycle/number of females cycling.

Table D-3 Results of Vaginal Cytology Study Using the Transition Matrix Approach in Female Rats in the Three-month Gavage Study of Tetrabromobisphenol A-bis(2,3-dibromopropyl ether)

Stage | Comparison | P Value | Trend^a^
Overall tests | Overall | 1
Overall tests | 250 mg/kg vs. vehicle controls | 0.971 | N
Overall tests | 500 mg/kg vs. vehicle controls | 0.996 | N
Overall tests | 1,000 mg/kg vs. vehicle controls | 0.996 | N
Extended estrus | Overall | 0.945
Extended estrus | 250 mg/kg vs. vehicle controls | 0.702 | N
Extended estrus | 500 mg/kg vs. vehicle controls | 0.702 | N
Extended estrus | 1,000 mg/kg vs. vehicle controls | 0.864 | –
Extended diestrus | Overall | 0.999
Extended diestrus | 250 mg/kg vs. vehicle controls | 0.933 | –
Extended diestrus | 500 mg/kg vs. vehicle controls | 0.958 | –
Extended diestrus | 1,000 mg/kg vs. vehicle controls | 0.948 | N
Extended metestrus | Overall | 1
Extended metestrus | 250 mg/kg vs. vehicle controls | 1 | –
Extended metestrus | 500 mg/kg vs. vehicle controls | 1 | –
Extended metestrus | 1,000 mg/kg vs. vehicle controls | 1 | –
Extended proestrus | Overall | 1
Extended proestrus | 250 mg/kg vs. vehicle controls | 1 | –
Extended proestrus | 500 mg/kg vs. vehicle controls | 1 | –
Extended proestrus | 1,000 mg/kg vs. vehicle controls | 1 | –
Skipped estrus | Overall | 1
Skipped estrus | 250 mg/kg vs. vehicle controls | 1 | –
Skipped estrus | 500 mg/kg vs. vehicle controls | 1 | –
Skipped estrus | 1,000 mg/kg vs. vehicle controls | 1 | –
Skipped diestrus | Overall | 1
Skipped diestrus | 250 mg/kg vs. vehicle controls | 1 | –
Skipped diestrus | 500 mg/kg vs. vehicle controls | 1 | –
Skipped diestrus | 1,000 mg/kg vs. vehicle controls | 1 | –

^a^ N means that the dosed group had a lower probability of transitioning to the relevant abnormal state (extended estrus, extended diestrus, extended metestrus, extended proestrus, skipped estrus, or skipped diestrus) than did the vehicle control group.

Table D-4 Summary of Reproductive Tissue Evaluations for Male Mice in the Three-month Gavage Study of Tetrabromobisphenol A-bis(2,3-dibromopropyl ether)^a^

| Vehicle Control | 500 mg/kg | 1,000 mg/kg | 2,000 mg/kg
n | 10 | 10 | 10 | 10
Weights (g)
Necropsy body wt | 36.8 ± 1.0 | 39.4 ± 1.5 | 38.2 ± 0.9 | 39.1 ± 1.1
L. Cauda epididymis | 0.0152 ± 0.0006 | 0.0167 ± 0.0016 | 0.0146 ± 0.0005 | 0.0149 ± 0.0008
L. Epididymis | 0.0428 ± 0.0009 | 0.0449 ± 0.0014 | 0.0433 ± 0.0011 | 0.0405 ± 0.0009
L. Testis | 0.1102 ± 0.0016 | 0.1139 ± 0.0023 | 0.1135 ± 0.0027 | 0.1096 ± 0.0015
Spermatid measurements
Spermatid heads (10^6^/g testis) | 210.0 ± 6.3 | 230.9 ± 11.8 | 221.7 ± 13.9 | 230.2 ± 7.1
Spermatid heads (10^6^/testis) | 21.4 ± 0.8 | 23.7 ± 1.1 | 22.9 ± 1.6 | 22.3 ± 0.8
Epididymal spermatozoal measurements
Sperm motility (%) | 86 ± 1 | 85 ± 1 | 85 ± 1 | 85 ± 1
Sperm (10^6^/g cauda epididymis) | 1,477.4 ± 147.4 | 1,448.0 ± 139.8 | 1,391.0 ± 132.9 | 1,672.3 ± 153.7
Sperm (10^6^/cauda epididymis) | 22.3 ± 2.2 | 22.9 ± 1.6 | 20.5 ± 2.2 | 24.8 ± 2.3

^a^ Data are presented as mean ± standard error. Differences from the vehicle control group are not significant by Dunnett’s test (body and tissue weights) or Dunn’s test (spermatid and epididymal spermatozoal measurements).

Table D-5 Estrous Cycle Characterization for Female Mice in the Three-month Gavage Study of Tetrabromobisphenol A-bis(2,3-dibromopropyl ether)^a^

| Vehicle Control | 500 mg/kg | 1,000 mg/kg | 2,000 mg/kg
Number weighed at necropsy | 10 | 10 | 10 | 10
Necropsy body wt (g) | 29.2 ± 1.0 | 31.0 ± 0.8 | 31.0 ± 0.8 | 30.2 ± 0.9
Proportion of regular cycling females^b^ | 8/9 | 9/10 | 7/9 | 8/9
Estrous cycle length (days) | 4.6 ± 0.18^c^ | 5.2 ± 0.44 | 4.5 ± 0.17^c^ | 4.5 ± 0.17^c^
Estrous stages (% of cycle)
Diestrus | 35.8 | 39.2 | 46.7 | 38.3
Proestrus | 0.0 | 0. 0 | 0.0 | 0.0
Estrus | 44.2 | 39.2 | 35.8 | 39.2
Metestrus | 19.2 | 21.7 | 17.5 | 22.5
Uncertain diagnosis | 0.8 | 0.0 | 0.0 | 0.0

^a^ Necropsy body weights and estrous cycle length data are presented as mean ± standard error. Differences from the vehicle control group are not significant by Dunnett’s test (body weight) or Dunn’s test (estrous cycle length). Tests for equality of transition probability matrices among all groups and between the vehicle control group and each dosed group indicated that 1,000 mg/kg females spent significantly more time in extended diestrus (P = 0.004) than did the vehicle control group.

^b^ Number of females with a regular cycle/number of females cycling.

^c^ Estrous cycle unclear in 1 of 10 animals.

Table D-6 Results of Vaginal Cytology Study Using the Transition Matrix Approach in Female Mice in the Three-month Gavage Study of Tetrabromobisphenol A-bis(2,3-dibromopropyl ether)

Stage | Comparison | P Value | Trend^a^
Overall tests | Overall | 0.636
Overall tests | 500 mg/kg vs. Vehicle Controls | 0.368 | –
Overall tests | 1,000 mg/kg vs. Vehicle Controls | 0.719 | –
Overall tests | 2,000 mg/kg vs. Vehicle Controls | 0.44 | –
Extended estrus | Overall | 0.579
Extended estrus | 500 mg/kg vs. Vehicle Controls | 0.351 | N
Extended estrus | 1,000 mg/kg vs. Vehicle Controls | 0.351 | N
Extended estrus | 2,000 mg/kg vs. Vehicle Controls | 0.764 | N
Extended diestrus | Overall | 0.001
Extended diestrus | 500 mg/kg vs. Vehicle Controls | 0.06 | –
Extended diestrus | 1,000 mg/kg vs. Vehicle Controls | 0.004 | –
Extended diestrus | 2,000 mg/kg vs. Vehicle Controls | 0.069 | –
Extended metestrus | Overall | 1
Extended metestrus | 500 mg/kg vs. Vehicle Controls | 1 | –
Extended metestrus | 1,000 mg/kg vs. Vehicle Controls | 1 | –
Extended metestrus | 2,000 mg/kg vs. Vehicle Controls | 1 | –
Extended proestrus | Overall | 1
Extended proestrus | 500 mg/kg vs. Vehicle Controls | 1 | –
Extended proestrus | 1,000 mg/kg vs. Vehicle Controls | 1 | –
Extended proestrus | 2,000 mg/kg vs. Vehicle Controls | 1 | –
Skipped estrus | Overall | 1
Skipped estrus | 500 mg/kg vs. Vehicle Controls | 1 | –
Skipped estrus | 1,000 mg/kg vs. Vehicle Controls | 1 | –
Skipped estrus | 2,000 mg/kg vs. Vehicle Controls | 1 | –
Skipped diestrus | Overall | 1
Skipped diestrus | 500 mg/kg vs. Vehicle Controls | 1 | –
Skipped diestrus | 1,000 mg/kg vs. Vehicle Controls | 1 | –
Skipped diestrus | 2,000 mg/kg vs. Vehicle Controls | 1 | –
Summary of Significant Groups
Extended diestrus | 1,000 mg/kg vs. Vehicle Controls | 0.004 | –

^a^ N means that the dosed group had a lower probability of transitioning to the relevant abnormal state (extended estrus, extended diestrus, extended metestrus, extended proestrus, skipped estrus, or skipped diestrus) than did the vehicle control group.

Figure D-1

Vaginal Cytology Plots for Female Rats in the Three-month Gavage Study of Tetrabromobisphenol A-bis(2,3-dibromopropyl ether)

Daily vaginal lavage samples were collected from each animal, and estrous stage was determined based on vaginal cytology. Individual females are aligned by their second estrus and color coded based on estrous stage to aid in visual comparisons amongst the groups. D = diestrus, P = proestrus, E = estrus, M = metestrus.

Figure D-2

Vaginal Cytology Plots for Female Mice in the Three-month Gavage Study of Tetrabromobisphenol A-bis(2,3-dibromopropyl ether)

Daily vaginal lavage samples were collected from each animal, and estrous stage was determined based on vaginal cytology. Individual females are aligned by their second estrus and color coded based on estrous stage to aid in visual comparisons amongst the groups. D = diestrus, P = proestrus, E = estrus, M = metestrus, IC = insufficient number of cells to determine stage.