# Appendix C Organ Weights and Organ-Weight-To-Body-Weight Ratios

Table C-1 Organ Weights and Organ-Weight-to-Body-Weight Ratios for Rats in the Three-month Gavage Study of Tetrabromobisphenol A-bis(2,3-dibromopropyl ether)^a^

| Vehicle Control | 62.5 mg/kg | 125 mg/kg | 250 mg/kg | 500 mg/kg | 1,000 mg/kg
Male
n | 10 | 8 | 10 | 10 | 10 | 10
Necropsy body wt | 330 ± 9 | 344 ± 8 | 329 ± 7 | 342 ± 6 | 333 ± 5 | 320 ± 8
Heart
Absolute | 0.93 ± 0.03 | 0.99 ± 0.04 | 0.95 ± 0.03 | 1.00 ± 0.03 | 0.92 ± 0.02 | 0.90 ± 0.02
Relative | 2.81 ± 0.03 | 2.87 ± 0.07 | 2.89 ± 0.04 | 2.92 ± 0.08 | 2.75 ± 0.05 | 2.82 ± 0.04
R. Kidney
Absolute | 0.83 ± 0.02 | 0.89 ± 0.02 | 0.85 ± 0.02 | 0.92 ± 0.02* | 0.83 ± 0.02 | 0.83 ± 0.03
Relative | 2.54 ± 0.05 | 2.59 ± 0.05 | 2.58 ± 0.05 | 2.70 ± 0.05 | 2.49 ± 0.05 | 2.58 ± 0.04
Liver
Absolute | 10.36 ± 0.31 | 11.65 ± 0.25* | 10.58 ± 0.27 | 11.40 ± 0.25 | 10.72 ± 0.29 | 10.82 ± 0.37
Relative | 31.43 ± 0.53 | 33.89 ± 0.45** | 32.12 ± 0.37 | 33.37 ± 0.35* | 32.18 ± 0.51 | 33.77 ± 0.44**
Lung
Absolute | 2.13 ± 0.12 | 1.94 ± 0.11 | 2.10 ± 0.17 | 2.38 ± 0.20 | 2.05 ± 0.08 | 2.16 ± 0.13
Relative | 6.46 ± 0.34 | 5.63 ± 0.29 | 6.35 ± 0.46 | 6.94 ± 0.53 | 6.19 ± 0.30 | 6.75 ± 0.37
Spleen
Absolute | 0.605 ± 0.014 | 0.617 ± 0.011 | 0.596 ± 0.017 | 0.631 ± 0.009 | 0.571 ± 0.014 | 0.586 ± 0.014
Relative | 1.84 ± 0.03 | 1.80 ± 0.03 | 1.81 ± 0.04 | 1.85 ± 0.04 | 1.72 ± 0.04 | 1.84 ± 0.05
R. Testis
Absolute | 1.357 ± 0.022 | 1.356 ± 0.027 | 1.336 ± 0.011 | 1.393 ± 0.022 | 1.321 ± 0.024 | 1.331 ± 0.041
Relative | 4.134 ± 0.086 | 3.945 ± 0.050 | 4.069 ± 0.079 | 4.090 ± 0.102 | 3.972 ± 0.063 | 4.162 ± 0.086
Thymus
Absolute | 0.341 ± 0.009 | 0.354 ± 0.022 | 0.343 ± 0.010 | 0.329 ± 0.017 | 0.296 ± 0.012 | 0.310 ± 0.013
Relative | 1.035 ± 0.020 | 1.031 ± 0.068 | 1.044 ± 0.033 | 0.964 ± 0.051 | 0.891 ± 0.035 | 0.972 ± 0.044
Female
n | 9 | 10 | 10 | 10 | 10 | 10
Necropsy body wt | 191 ± 4 | 195 ± 4 | 188 ± 4 | 194 ± 4 | 188 ± 3 | 190 ± 4
Heart
Absolute | 0.65 ± 0.01 | 0.65 ± 0.02 | 0.63 ± 0.02 | 0.65 ± 0.02 | 0.61 ± 0.01 | 0.64 ± 0.01
Relative | 3.39 ± 0.07 | 3.33 ± 0.08 | 3.33 ± 0.06 | 3.34 ± 0.07 | 3.25 ± 0.06 | 3.37 ± 0.07
R. Kidney
Absolute | 0.55 ± 0.01 | 0.56 ± 0.02 | 0.55 ± 0.01 | 0.56 ± 0.01 | 0.52 ± 0.01 | 0.55 ± 0.01
Relative | 2.87 ± 0.04 | 2.85 ± 0.06 | 2.90 ± 0.05 | 2.89 ± 0.04 | 2.79 ± 0.05 | 2.88 ± 0.04
Liver
Absolute | 5.91 ± 0.14 | 6.21 ± 0.14 | 6.09 ± 0.14 | 6.18 ± 0.12 | 5.90 ± 0.09 | 6.25 ± 0.12
Relative | 30.93 ± 0.46 | 31.88 ± 0.52 | 32.37 ± 0.38 | 31.92 ± 0.44 | 31.47 ± 0.53 | 33.03 ± 0.23**
Lung
Absolute | 1.56 ± 0.18 | 1.39 ± 0.09 | 1.40 ± 0.11 | 1.56 ± 0.10 | 1.32 ± 0.06 | 1.43 ± 0.08
Relative | 8.14 ± 0.88 | 7.13 ± 0.44 | 7.47 ± 0.58 | 8.05 ± 0.50 | 7.09 ± 0.37 | 7.56 ± 0.46
Spleen
Absolute | 0.433 ± 0.009 | 0.462 ± 0.018 | 0.459 ± 0.011 | 0.467 ± 0.013 | 0.447 ± 0.009 | 0.476 ± 0.014
Relative | 2.27 ± 0.06 | 2.37 ± 0.09 | 2.45 ± 0.06 | 2.41 ± 0.06 | 2.39 ± 0.07 | 2.52 ± 0.08
Thymus
Absolute | 0.244 ± 0.009 | 0.250 ± 0.010 | 0.258 ± 0.008 | 0.267 ± 0.021 | 0.237 ± 0.008 | 0.264 ± 0.012
Relative | 1.277 ± 0.041 | 1.287 ± 0.052 | 1.371 ± 0.027 | 1.369 ± 0.096 | 1.268 ± 0.050 | 1.397 ± 0.072

* Significantly different (P ≤ 0.05) from the vehicle control group by Dunnett’s test.

** P ≤ 0.01.

^a^ Organ weights (absolute weights) and body weights are given in grams; organ-weight-to-body-weight ratios (relative weights) are given as mg organ weight/g body weight (mean ± standard error).

Table C-2 Organ Weights and Organ-Weight-to-Body-Weight Ratios for Mice in the Three-month Gavage Study of Tetrabromobisphenol A-bis(2,3-dibromopropyl ether)^a^

| Vehicle Control | 125 mg/kg | 250 mg/kg | 500 mg/kg | 1,000 mg/kg | 2,000 mg/kg
n | 10 | 10 | 10 | 10 | 10 | 10
Male
Necropsy body wt | 36.8 ± 1.0 | 39.0 ± 0.9 | 38.3 ± 1.0 | 39.4 ± 1.5 | 38.2 ± 0.9 | 39.1 ± 1.1
Heart
Absolute | 0.18 ± 0.01 | 0.18 ± 0.01 | 0.20 ± 0.01 | 0.19 ± 0.01 | 0.19 ± 0.01 | 0.19 ± 0.01
Relative | 4.90 ± 0.16 | 4.58 ± 0.13 | 5.10 ± 0.16 | 4.94 ± 0.15 | 5.09 ± 0.19 | 4.82 ± 0.16
R. Kidney
Absolute | 0.27 ± 0.01 | 0.28 ± 0.01 | 0.28 ± 0.01 | 0.28 ± 0.01 | 0.28 ± 0.01 | 0.27 ± 0.01
Relative | 7.33 ± 0.23 | 7.15 ± 0.12 | 7.36 ± 0.18 | 7.14 ± 0.19 | 7.23 ± 0.15 | 6.86 ± 0.14
Liver
Absolute | 1.43 ± 0.07 | 1.62 ± 0.03 | 1.58 ± 0.06 | 1.67 ± 0.13 | 1.58 ± 0.04 | 1.62 ± 0.08
Relative | 38.91 ± 1.44 | 41.67 ± 0.93 | 41.36 ± 1.02 | 42.05 ± 1.76 | 41.29 ± 0.56 | 41.22 ± 1.06
Lung
Absolute | 0.32 ± 0.01 | 0.33 ± 0.01 | 0.34 ± 0.02 | 0.32 ± 0.01 | 0.32 ± 0.01 | 0.32 ± 0.01
Relative | 8.85 ± 0.41 | 8.44 ± 0.23 | 8.83 ± 0.42 | 8.08 ± 0.31 | 8.49 ± 0.23 | 8.25 ± 0.22
Spleen
Absolute | 0.063 ± 0.001 | 0.065 ± 0.002 | 0.067 ± 0.002 | 0.067 ± 0.003 | 0.066 ± 0.001 | 0.061 ± 0.001
Relative | 1.71 ± 0.03 | 1.67 ± 0.04 | 1.75 ± 0.06 | 1.70 ± 0.04 | 1.73 ± 0.05 | 1.58 ± 0.03
R. Testis
Absolute | 0.118 ± 0.002 | 0.118 ± 0.002 | 0.116 ± 0.003 | 0.118 ± 0.002 | 0.118 ± 0.002 | 0.116 ± 0.002
Relative | 3.244 ± 0.118 | 3.047 ± 0.072 | 3.049 ± 0.068 | 3.014 ± 0.091 | 3.099 ± 0.082 | 2.981 ± 0.060
Thymus
Absolute | 0.053 ± 0.005 | 0.054 ± 0.004 | 0.051 ± 0.003 | 0.054 ± 0.004 | 0.051 ± 0.002 | 0.054 ± 0.006
Relative | 1.427 ± 0.103 | 1.388 ± 0.085 | 1.342 ± 0.061 | 1.368 ± 0.056 | 1.326 ± 0.040 | 1.356 ± 0.120
Female
Necropsy body wt | 29.2 ± 1.0 | 31.6 ± 1.3 | 32.4 ± 0.7 | 31.0 ± 0.8 | 31.0 ± 0.8 | 30.2 ± 0.9
Heart
Absolute | 0.14 ± 0.00 | 0.14 ± 0.01 | 0.14 ± 0.00 | 0.15 ± 0.01 | 0.14 ± 0.00 | 0.14 ± 0.01
Relative | 4.72 ± 0.22 | 4.47 ± 0.22 | 4.49 ± 0.18 | 4.78 ± 0.18 | 4.64 ± 0.13 | 4.77 ± 0.17
R. Kidney
Absolute | 0.17 ± 0.00 | 0.17 ± 0.01 | 0.17 ± 0.01 | 0.16 ± 0.00 | 0.16 ± 0.01 | 0.16 ± 0.01
Relative | 5.66 ± 0.13 | 5.26 ± 0.10 | 5.26 ± 0.14 | 5.31 ± 0.13 | 5.29 ± 0.07 | 5.33 ± 0.18
Liver
Absolute | 1.10 ± 0.02 | 1.22 ± 0.05* | 1.25 ± 0.03** | 1.16 ± 0.03 | 1.21 ± 0.04 | 1.22 ± 0.03*
Relative | 37.75 ± 1.14 | 38.79 ± 1.18 | 38.75 ± 0.85 | 37.55 ± 0.64 | 38.88 ± 0.41 | 40.57 ± 1.16
Lung
Absolute | 0.29 ± 0.02 | 0.30 ± 0.01 | 0.31 ± 0.01 | 0.31 ± 0.01 | 0.30 ± 0.01 | 0.30 ± 0.01
Relative | 9.99 ± 0.42 | 9.54 ± 0.52 | 9.64 ± 0.27 | 10.10 ± 0.17 | 9.83 ± 0.36 | 9.76 ± 0.27
Spleen
Absolute | 0.080 ± 0.002 | 0.081 ± 0.003 | 0.084 ± 0.003 | 0.084 ± 0.003 | 0.083 ± 0.003 | 0.081 ± 0.002
Relative | 2.76 ± 0.10 | 2.58 ± 0.09 | 2.61 ± 0.11 | 2.72 ± 0.10 | 2.66 ± 0.06 | 2.70 ± 0.10
Thymus
Absolute | 0.050 ± 0.003 | 0.058 ± 0.002 | 0.057 ± 0.002 | 0.052 ± 0.002 | 0.054 ± 0.002 | 0.054 ± 0.002
Relative | 1.719 ± 0.088 | 1.855 ± 0.074 | 1.774 ± 0.060 | 1.681 ± 0.067 | 1.739 ± 0.048 | 1.819 ± 0.094

* Significantly different (P ≤ 0.05) from the vehicle control group by Dunnett’s test.

** P ≤ 0.01.

^a^ Organ weights (absolute weights) and body weights are given in grams; organ-weight-to-body-weight ratios (relative weights) are given as mg organ weight/g body weight (mean ± standard error).