# Appendix B Clinical Pathology Results

Table B-1 Hematology and Clinical Chemistry Data for Rats in the Three-month Gavage Study of Tetrabromobisphenol A-bis(2,3-dibromopropyl ether)^a^

| Vehicle Control | 62.5 mg/kg | 125 mg/kg | 250 mg/kg | 500 mg/kg | 1,000 mg/kg
Male
Hematology
n
Day 23 | 10 | 9 | 10 | 10 | 10 | 8
Week 14 | 8 | 7 | 8 | 10 | 10 | 9
Hematocrit (%)
Day 23 | 50.1 ± 0.6 | 50.5 ± 0.9 | 50.9 ± 1.0 | 50.3 ± 0.7 | 51.1 ± 1.6 | 50.4 ± 1.6
Week 14 | 49.0 ± 0.6 | 47.8 ± 0.4 | 47.7 ± 0.5 | 48.1 ± 1.0 | 47.5 ± 0.5 | 47.1 ± 0.4
Hemoglobin (g/dL)
Day 23 | 15.4 ± 0.2 | 15.4 ± 0.3 | 15.6 ± 0.2 | 15.4 ± 0.2 | 15.5 ± 0.4 | 15.3 ± 0.4
Week 14 | 15.4 ± 0.2 | 15.1 ± 0.1 | 14.9 ± 0.1 | 15.1 ± 0.3 | 15.0 ± 0.1 | 14.8 ± 0.1
Erythrocytes (10^6^/μL)
Day 23 | 8.38 ± 0.08 | 8.50 ± 0.14 | 8.62 ± 0.12 | 8.56 ± 0.12 | 8.64 ± 0.26 | 8.58 ± 0.25
Week 14 | 9.56 ± 0.09 | 9.37 ± 0.04 | 9.39 ± 0.09 | 9.46 ± 0.13 | 9.41 ± 0.08 | 9.28 ± 0.09
Reticulocytes (10^3^/μL)
Day 23 | 370 ± 17 | 379 ± 13 | 408 ± 16 | 382 ± 8 | 408 ± 10 | 415 ± 14
Week 14 | 173 ± 19 | 193 ± 12 | 186 ± 10 | 192 ± 8 | 172 ± 10 | 197 ± 3
Mean cell volume (fL)
Day 23 | 59.8 ± 0.3 | 59.4 ± 0.4 | 59.0 ± 0.4 | 58.8 ± 0.3 | 59.1 ± 0.2 | 58.7 ± 0.4
Week 14 | 51.3 ± 0.2 | 51.0 ± 0.4 | 50.8 ± 0.3 | 50.8 ± 0.4 | 50.6 ± 0.3 | 50.8 ± 0.4
Mean cell hemoglobin (pg)
Day 23 | 18.4 ± 0.1 | 18.2 ± 0.1 | 18.1 ± 0.1* | 18.0 ± 0.1** | 18.0 ± 0.1** | 17.8 ± 0.1**
Week 14 | 16.1 ± 0.1 | 16.2 ± 0.2 | 15.8 ± 0.1 | 15.9 ± 0.1 | 16.0 ± 0.1 | 16.0 ± 0.1
Mean cell hemoglobin concentration (g/dL)
Day 23 | 30.8 ± 0.2 | 30.6 ± 0.2 | 30.6 ± 0.2 | 30.6 ± 0.1 | 30.4 ± 0.1 | 30.3 ± 0.2
Week 14 | 31.4 ± 0.2 | 31.7 ± 0.2 | 31.2 ± 0.1 | 31.4 ± 0.2 | 31.6 ± 0.2 | 31.4 ± 0.1
Platelets (10^3^/μL)
Day 23 | 914 ± 26 | 937 ± 41 | 987 ± 32 | 960 ± 19 | 893 ± 67 | 1,004 ± 27
Week 14 | 754 ± 21 | 815 ± 15 | 838 ± 19* | 783 ± 20 | 781 ± 36 | 834 ± 9*
Leukocytes (10^3^/μL)
Day 23 | 7.82 ± 0.24 | 8.66 ± 0.38 | 8.42 ± 0.54 | 8.14 ± 0.19 | 8.87 ± 0.31 | 8.64 ± 0.66
Week 14 | 7.06 ± 0.51 | 7.15 ± 0.53 | 6.92 ± 0.34 | 7.24 ± 0.36 | 6.77 ± 0.54 | 6.95 ± 0.44
Segmented neutrophils (10^3^/μL)
Day 23 | 1.48 ± 0.12 | 1.98 ± 0.20 | 1.56 ± 0.11 | 1.52 ± 0.12 | 2.13 ± 0.10** | 1.95 ± 0.15
Week 14 | 1.33 ± 0.11 | 1.49 ± 0.16 | 1.68 ± 0.14 | 1.52 ± 0.13 | 1.50 ± 0.13 | 1.36 ± 0.12
Lymphocytes (10^3^/μL)
Day 23 | 6.01 ± 0.17 | 6.31 ± 0.28 | 6.55 ± 0.44 | 6.32 ± 0.22 | 6.25 ± 0.30 | 6.31 ± 0.50
Week 14 | 5.45 ± 0.52 | 5.39 ± 0.43 | 4.98 ± 0.30 | 5.43 ± 0.27 | 4.99 ± 0.44 | 5.35 ± 0.38
Monocytes (10^3^/μL)
Day 23 | 0.20 ± 0.01 | 0.23 ± 0.02 | 0.22 ± 0.02 | 0.21 ± 0.02 | 0.24 ± 0.02 | 0.25 ± 0.03
Week 14 | 0.15 ± 0.02 | 0.15 ± 0.02 | 0.15 ± 0.02 | 0.15 ± 0.01 | 0.15 ± 0.02 | 0.14 ± 0.02
Basophils (10^3^/μL)
Day 23 | 0.080 ± 0.015 | 0.073 ± 0.011 | 0.059 ± 0.011 | 0.044 ± 0.007 | 0.106 ± 0.020 | 0.090 ± 0.029
Week 14 | 0.025 ± 0.004 | 0.026 ± 0.004 | 0.030 ± 0.005 | 0.025 ± 0.003 | 0.027 ± 0.006 | 0.024 ± 0.003
Eosinophils (10^3^/μL)
Day 23 | 0.05 ± 0.02 | 0.07 ± 0.02 | 0.04 ± 0.01 | 0.05 ± 0.01 | 0.14 ± 0.03* | 0.05 ± 0.01
Week 14 | 0.11 ± 0.01 | 0.10 ± 0.01 | 0.08 ± 0.01 | 0.12 ± 0.02 | 0.11 ± 0.01 | 0.08 ± 0.01
Clinical Chemistry
n
Day 4 | 10 | 10 | 10 | 10 | 10 | 10
Day 23 | 10 | 10 | 10 | 10 | 9 | 9
Week 14 | 10 | 8 | 10 | 10 | 10 | 10
Urea nitrogen (mg/dL)
Day 4 | 10.1 ± 0.6^b^ | 10.5 ± 0.7 | 10.1 ± 0.5^b^ | 10.4 ± 0.6^b^ | 10.9 ± 0.6^b^ | 11.0 ± 0.6
Day 23 | 10.9 ± 0.3 | 11.3 ± 0.5 | 9.6 ± 0.5 | 11.6 ± 0.5 | 11.6 ± 0.4 | 10.9 ± 0.8
Week 14 | 15.1 ± 0.8 | 15.6 ± 1.0 | 12.9 ± 0.5 | 11.5 ± 0.5** | 16.1 ± 0.6 | 14.4 ± 0.7
Creatinine (mg/dL)
Day 4 | 0.50 ± 0.00^b^ | 0.50 ± 0.00 | 0.47 ± 0.02^b^ | 0.49 ± 0.01^b^ | 0.49 ± 0.01^b^ | 0.45 ± 0.02**
Day 23 | 0.60 ± 0.02 | 0.55 ± 0.02 | 0.56 ± 0.02 | 0.57 ± 0.03 | 0.56 ± 0.02 | 0.54 ± 0.02
Week 14 | 0.80 ± 0.01 | 0.78 ± 0.02 | 0.75 ± 0.02 | 0.74 ± 0.02 | 0.77 ± 0.02 | 0.74 ± 0.02
Glucose (mg/dL)
Day 4 | 123 ± 2^b^ | 122 ± 2 | 119 ± 3^b^ | 123 ± 4^b^ | 121 ± 2^b^ | 123 ± 3
Day 23 | 165 ± 5 | 157 ± 6 | 162 ± 7 | 155 ± 7 | 153 ± 4 | 159 ± 4
Week 14 | 263 ± 8 | 244 ± 10 | 255 ± 11 | 268 ± 13 | 257 ± 7 | 249 ± 10
Total protein (g/dL)
Day 4 | 5.9 ± 0.1^b^ | 5.9 ± 0.1 | 5.9 ± 0.1^b^ | 5.9 ± 0.1^b^ | 5.8 ± 0.1^b^ | 5.9 ± 0.1
Day 23 | 6.3 ± 0.1 | 6.5 ± 0.1 | 6.3 ± 0.1 | 6.5 ± 0.1 | 6.4 ± 0.1 | 6.4 ± 0.1
Week 14 | 7.2 ± 0.1 | 7.1 ± 0.1 | 7.0 ± 0.1 | 6.9 ± 0.1 | 7.1 ± 0.1 | 7.0 ± 0.1
Albumin (g/dL)
Day 4 | 4.3 ± 0.0^b^ | 4.2 ± 0.1 | 4.3 ± 0.1^b^ | 4.3 ± 0.1^b^ | 4.2 ± 0.0^b^ | 4.3 ± 0.0
Day 23 | 4.2 ± 0.0 | 4.4 ± 0.0* | 4.3 ± 0.1 | 4.4 ± 0.1* | 4.4 ± 0.1* | 4.4 ± 0.1
Week 14 | 4.6 ± 0.1 | 4.6 ± 0.1 | 4.4 ± 0.0 | 4.4 ± 0.1 | 4.5 ± 0.1 | 4.5 ± 0.1
Cholesterol (mg/dL)
Day 4 | 98 ± 3 | 89 ± 2 | 94 ± 3 | 89 ± 2* | 87 ± 3** | 85 ± 3**
Day 23 | 88 ± 2 | 80 ± 2 | 79 ± 2 | 81 ± 2 | 77 ± 2* | 81 ± 2
Week 14 | 76 ± 3 | 75 ± 3 | 69 ± 2 | 64 ± 2** | 70 ± 2 | 67 ± 4
Alanine aminotransferase (IU/L)
Day 4 | 73 ± 2 | 71 ± 2 | 69 ± 2 | 73 ± 3 | 71 ± 2 | 71 ± 2
Day 23 | 56 ± 2 | 64 ± 1* | 60 ± 1 | 63 ± 2 | 62 ± 2 | 63 ± 2
Week 14 | 116 ± 23 | 83 ± 8 | 76 ± 10 | 84 ± 13 | 96 ± 6 | 75 ± 6
Alkaline phosphatase (IU/L)
Day 4 | 665 ± 12 | 640 ± 14 | 639 ± 16 | 620 ± 9 | 629 ± 13 | 611 ± 17
Day 23 | 524 ± 10 | 528 ± 12 | 544 ± 14 | 521 ± 15 | 517 ± 13 | 511 ± 16
Week 14 | 275 ± 8 | 263 ± 6 | 257 ± 8 | 258 ± 10 | 294 ± 7 | 265 ± 8
Creatine kinase (IU/L)
Day 4 | 441 ± 35^b^ | 646 ± 186 | 364 ± 34^b^ | 545 ± 48^b^ | 623 ± 77^b^ | 469 ± 40
Day 23 | 615 ± 89 | 559 ± 55 | 458 ± 75 | 467 ± 64 | 491 ± 48 | 725 ± 125
Week 14 | 360 ± 130 | 142 ± 17 | 224 ± 52 | 248 ± 50 | 112 ± 4** | 140 ± 9
Sorbitol dehydrogenase (IU/L)
Day 4 | 15 ± 1 | 14 ± 1 | 15 ± 1 | 13 ± 1 | 13 ± 1 | 14 ± 1
Day 23 | 18 ± 1 | 19 ± 2 | 15 ± 1* | 16 ± 1 | 15 ± 1 | 16 ± 1
Week 14 | 44 ± 13 | 29 ± 3 | 31 ± 8 | 46 ± 15 | 28 ± 1 | 25 ± 2*
Bile acids (µmol/L)
Day 4 | 16.9 ± 2.6 | 12.9 ± 1.4 | 17.0 ± 3.6 | 13.6 ± 2.5 | 9.6 ± 1.6 | 14.7 ± 1.4
Day 23 | 9.6 ± 1.0 | 13.8 ± 1.9 | 14.1 ± 1.1 | 11.5 ± 1.6 | 9.3 ± 1.3 | 10.2 ± 1.4
Week 14 | 19.7 ± 2.3 | 17.6 ± 3.1 | 17.7 ± 2.6 | 20.4 ± 2.5 | 16.0 ± 1.8 | 15.6 ± 1.7
Total thyroxine (µg/dL)
Day 4 | 7.05 ± 0.26 | 6.61 ± 0.24 | 6.58 ± 0.29 | 6.31 ± 0.29 | 6.50 ± 0.30 | 6.05 ± 0.22
Day 23 | 6.45 ± 0.19 | 6.88 ± 0.18 | 6.65 ± 0.27 | 6.83 ± 0.23 | 7.14 ± 0.34^c^ | 6.51 ± 0.14
Week 14 | 3.16 ± 0.25 | 3.53 ± 0.29 | 2.88 ± 0.20 | 3.24 ± 0.28 | 3.17 ± 0.20 | 2.98 ± 0.16
Total triiodothyronine (ng/dL)
Day 23 | 158.3 ± 4.3 | 164.2 ± 8.9 | 155.1 ± 7.7 | 175.9 ± 6.8 | 170.6 ± 8.5^c^ | 162.6 ± 9.2
Week 14 | 109.0 ± 9.2^b^ | 106.1 ± 5.8 | 99.9 ± 6.2^b^ | 109.5 ± 5.6 | 91.2 ± 7.9 | 97.9 ± 9.2
Thyroid stimulating hormone (ng/mL)
Day 4 | 6.36 ± 0.28 | 6.47 ± 0.81 | 6.44 ± 0.17 | 6.16 ± 0.41 | 5.79 ± 0.27 | 6.56 ± 0.61
Day 23 | 10.00 ± 0.68 | 10.05 ± 0.60 | 11.23 ± 1.51 | 11.32 ± 0.94^b^ | 9.38 ± 0.30 | 9.62 ± 0.36
Week 14 | 9.91 ± 0.53 | 9.96 ± 0.54 | 10.94 ± 0.80 | 11.28 ± 1.31 | 8.84 ± 0.76^b^ | 10.85 ± 0.79
Female
Hematology
n
Day 23 | 10 | 7 | 8 | 7 | 9 | 9
Week 14 | 9 | 10 | 10 | 10 | 10 | 10
Hematocrit (%)
Day 23 | 49.0 ± 0.7 | 49.9 ± 2.2 | 49.3 ± 1.4 | 49.2 ± 0.9 | 48.8 ± 0.4 | 47.5 ± 0.5
Week 14 | 45.9 ± 0.4 | 45.9 ± 0.3 | 45.6 ± 0.4 | 46.6 ± 0.6 | 45.3 ± 0.3 | 44.7 ± 0.4
Hemoglobin (g/dL)
Day 23 | 15.6 ± 0.2 | 15.8 ± 0.6 | 15.6 ± 0.4 | 15.7 ± 0.3 | 15.5 ± 0.1 | 15.1 ± 0.1
Week 14 | 15.0 ± 0.1 | 15.1 ± 0.1 | 14.7 ± 0.1 | 15.0 ± 0.2 | 14.6 ± 0.1* | 14.5 ± 0.1**
Erythrocytes (10^6^/μL)
Day 23 | 8.50 ± 0.14 | 8.65 ± 0.34 | 8.53 ± 0.19 | 8.58 ± 0.15 | 8.56 ± 0.05 | 8.36 ± 0.08
Week 14 | 8.57 ± 0.07 | 8.47 ± 0.05 | 8.54 ± 0.08 | 8.72 ± 0.10 | 8.55 ± 0.05 | 8.38 ± 0.09
Reticulocytes (10^3^/μL)
Day 23 | 194 ± 5 | 214 ± 16 | 208 ± 10 | 183 ± 3 | 209 ± 7 | 214 ± 10
Week 14 | 193 ± 7 | 194 ± 8 | 206 ± 9 | 184 ± 9 | 194 ± 7 | 209 ± 9
Mean cell volume (fL)
Day 23 | 57.6 ± 0.2 | 57.6 ± 0.3 | 57.8 ± 0.4 | 57.4 ± 0.2 | 57.0 ± 0.3 | 56.8 ± 0.3
Week 14 | 53.6 ± 0.3 | 54.2 ± 0.2 | 53.3 ± 0.4 | 53.5 ± 0.3 | 53.0 ± 0.2 | 53.3 ± 0.3
Mean cell hemoglobin (pg)
Day 23 | 18.4 ± 0.1 | 18.3 ± 0.1 | 18.3 ± 0.1 | 18.3 ± 0.1 | 18.1 ± 0.1 | 18.1 ± 0.1
Week 14 | 17.5 ± 0.1 | 17.8 ± 0.1 | 17.2 ± 0.1 | 17.3 ± 0.1 | 17.1 ± 0.1 | 17.3 ± 0.1
Mean cell hemoglobin concentration (g/dL)
Day 23 | 31.9 ± 0.1 | 31.8 ± 0.2 | 31.6 ± 0.2 | 31.9 ± 0.2 | 31.7 ± 0.2 | 31.9 ± 0.2
Week 14 | 32.7 ± 0.2 | 32.9 ± 0.2 | 32.3 ± 0.1 | 32.3 ± 0.2 | 32.3 ± 0.1 | 32.5 ± 0.1
Platelets (10^3^/μL)
Day 23 | 846 ± 37 | 873 ± 41 | 949 ± 30 | 880 ± 21 | 795 ± 80 | 941 ± 65
Week 14 | 787 ± 28 | 827 ± 43 | 916 ± 37* | 817 ± 57 | 883 ± 32 | 918 ± 47
Leukocytes (10^3^/μL)
Day 23 | 9.57 ± 0.41 | 9.94 ± 0.45 | 8.72 ± 0.53 | 9.52 ± 0.74 | 9.08 ± 0.48 | 9.63 ± 0.62
Week 14 | 8.33 ± 0.80 | 7.21 ± 0.26 | 7.57 ± 0.67 | 8.50 ± 0.56 | 7.86 ± 0.41 | 8.19 ± 0.37
Segmented neutrophils (10^3^/μL)
Day 23 | 1.65 ± 0.15 | 1.99 ± 0.15 | 1.72 ± 0.17 | 2.04 ± 0.22 | 2.09 ± 0.18 | 2.06 ± 0.18
Week 14 | 1.55 ± 0.12 | 1.37 ± 0.11 | 1.52 ± 0.14 | 1.59 ± 0.11 | 1.74 ± 0.11 | 1.77 ± 0.11
Lymphocytes (10^3^/μL)
Day 23 | 7.49 ± 0.32 | 7.47 ± 0.43 | 6.54 ± 0.39 | 6.99 ± 0.45 | 6.55 ± 0.41 | 7.15 ± 0.46
Week 14 | 6.32 ± 0.59 | 5.52 ± 0.23 | 5.75 ± 0.53 | 6.53 ± 0.49 | 5.78 ± 0.34 | 6.07 ± 0.30
Monocytes (10^3^/μL)
Day 23 | 0.25 ± 0.02 | 0.26 ± 0.03 | 0.23 ± 0.02 | 0.27 ± 0.04 | 0.25 ± 0.03 | 0.27 ± 0.02
Week 14 | 0.32 ± 0.13 | 0.18 ± 0.01 | 0.18 ± 0.02 | 0.22 ± 0.03 | 0.21 ± 0.02 | 0.22 ± 0.01
Basophils (10^3^/μL)
Day 23 | 0.102 ± 0.009 | 0.094 ± 0.023 | 0.106 ± 0.029 | 0.086 ± 0.014 | 0.084 ± 0.009 | 0.083 ± 0.010
Week 14 | 0.049 ± 0.009 | 0.050 ± 0.006 | 0.038 ± 0.006 | 0.066 ± 0.012 | 0.044 ± 0.004 | 0.052 ± 0.010
Eosinophils (10^3^/μL)
Day 23 | 0.09 ± 0.02 | 0.13 ± 0.03 | 0.12 ± 0.04 | 0.14 ± 0.05 | 0.11 ± 0.02 | 0.07 ± 0.01
Week 14 | 0.10 ± 0.01 | 0.09 ± 0.02 | 0.08 ± 0.01 | 0.09 ± 0.02 | 0.09 ± 0.02 | 0.07 ± 0.01
Clinical Chemistry
n
Day 4 | 10 | 10 | 10 | 10 | 10 | 9
Day 23 | 10 | 10 | 10 | 9 | 10 | 10
Week 14 | 8 | 9 | 10 | 10 | 10 | 10
Urea nitrogen (mg/dL)
Day 4 | 10.6 ± 0.6^b^ | 11.2 ± 0.9 | 11.6 ± 0.7^b^ | 10.4 ± 0.5 | 9.7 ± 0.6^b^ | 9.4 ± 0.6
Day 23 | 11.5 ± 0.5 | 12.0 ± 0.4^b^ | 12.1 ± 0.5 | 11.8 ± 0.9 | 12.0 ± 0.7 | 10.6 ± 0.5
Week 14 | 13.4 ± 0.5 | 14.9 ± 0.4 | 14.5 ± 0.5 | 13.1 ± 0.3 | 13.3 ± 0.5 | 14.3 ± 0.5
Creatinine (mg/dL)
Day 4 | 0.47 ± 0.02^b^ | 0.46 ± 0.02 | 0.46 ± 0.02^b^ | 0.43 ± 0.02 | 0.42 ± 0.01^b^ | 0.41 ± 0.01*
Day 23 | 0.58 ± 0.01 | 0.58 ± 0.02^b^ | 0.59 ± 0.01 | 0.59 ± 0.01 | 0.55 ± 0.02 | 0.57 ± 0.02
Week 14 | 0.70 ± 0.02 | 0.73 ± 0.03 | 0.70 ± 0.01 | 0.69 ± 0.02 | 0.69 ± 0.02 | 0.71 ± 0.02
Glucose (mg/dL)
Day 4 | 121 ± 3^b^ | 122 ± 3 | 121 ± 4^b^ | 113 ± 2 | 119 ± 3^b^ | 111 ± 3*
Day 23 | 137 ± 5 | 139 ± 5^b^ | 151 ± 7 | 146 ± 9 | 149 ± 4 | 131 ± 4
Week 14 | 215 ± 12 | 233 ± 14 | 218 ± 5 | 218 ± 7 | 212 ± 7 | 208 ± 8
Total protein (g/dL)
Day 4 | 5.9 ± 0.1^b^ | 5.9 ± 0.1 | 6.1 ± 0.1^b^ | 5.9 ± 0.1 | 5.8 ± 0.1^b^ | 5.8 ± 0.1
Day 23 | 6.2 ± 0.1 | 6.3 ± 0.1^b^ | 6.4 ± 0.1 | 6.4 ± 0.1 | 6.3 ± 0.1 | 6.3 ± 0.1
Week 14 | 6.7 ± 0.2 | 6.7 ± 0.1 | 6.5 ± 0.1 | 6.5 ± 0.1 | 6.4 ± 0.1 | 6.5 ± 0.1
Albumin (g/dL)
Day 4 | 4.3 ± 0.1^b^ | 4.3 ± 0.1 | 4.4 ± 0.1^b^ | 4.3 ± 0.0 | 4.2 ± 0.1^b^ | 4.3 ± 0.1
Day 23 | 4.5 ± 0.0 | 4.5 ± 0.1^b^ | 4.6 ± 0.1 | 4.5 ± 0.1 | 4.5 ± 0.1 | 4.5 ± 0.0
Week 14 | 4.6 ± 0.1 | 4.6 ± 0.1 | 4.5 ± 0.1 | 4.5 ± 0.1 | 4.5 ± 0.1 | 4.5 ± 0.1
Cholesterol (mg/dL)
Day 4 | 98 ± 3 | 93 ± 2 | 93 ± 2 | 92 ± 3 | 84 ± 2** | 89 ± 2**^c^
Day 23 | 87 ± 2 | 82 ± 2 | 83 ± 3 | 81 ± 2* | 74 ± 1** | 77 ± 2**
Week 14 | 74 ± 3 | 72 ± 2 | 67 ± 2 | 68 ± 2 | 64 ± 1** | 69 ± 2
Alanine aminotransferase (IU/L)
Day 4 | 63 ± 2 | 66 ± 2 | 67 ± 2 | 65 ± 3 | 60 ± 3 | 67 ± 12
Day 23 | 43 ± 2 | 47 ± 2 | 52 ± 2** | 53 ± 2** | 49 ± 1** | 51 ± 2**
Week 14 | 71 ± 16 | 87 ± 12* | 69 ± 5 | 72 ± 5 | 69 ± 8 | 70 ± 3
Alkaline phosphatase (IU/L)
Day 4 | 565 ± 16 | 552 ± 8 | 578 ± 12 | 550 ± 21 | 526 ± 15 | 509 ± 27
Day 23 | 382 ± 11 | 383 ± 8 | 425 ± 8** | 413 ± 9 | 388 ± 8 | 390 ± 9
Week 14 | 286 ± 9 | 279 ± 10 | 267 ± 12 | 270 ± 5 | 271 ± 8 | 246 ± 5**
Creatine kinase (IU/L)
Day 4 | 559 ± 37^d^ | 656 ± 88 | 545 ± 59^b^ | 661 ± 71 | 651 ± 77^b^ | 546 ± 62
Day 23 | 407 ± 56 | 583 ± 74^b^ | 617 ± 107 | 517 ± 78 | 516 ± 63 | 638 ± 79
Week 14 | 178 ± 43 | 318 ± 81 | 228 ± 76 | 180 ± 58 | 196 ± 45 | 174 ± 56
Sorbitol dehydrogenase (IU/L)
Day 4 | 9 ± 1 | 9 ± 1 | 9 ± 1 | 9 ± 1 | 9 ± 1 | 11 ± 2
Day 23 | 14 ± 1 | 13 ± 0 | 16 ± 1 | 14 ± 1 | 14 ± 1 | 13 ± 1
Week 14 | 40 ± 19 | 37 ± 11 | 25 ± 1 | 28 ± 1 | 26 ± 3 | 26 ± 2
Bile acids (µmol/L)
Day 4 | 9.6 ± 1.7 | 14.9 ± 3.2 | 11.2 ± 1.1 | 12.1 ± 2.3 | 9.2 ± 0.9 | 10.6 ± 2.4
Day 23 | 12.1 ± 1.5 | 8.9 ± 1.2 | 12.7 ± 3.4 | 14.7 ± 1.1 | 12.0 ± 2.8 | 13.1 ± 1.8
Week 14 | 25.5 ± 3.4 | 29.0 ± 4.7 | 29.5 ± 4.4 | 21.4 ± 3.5 | 25.5 ± 3.3 | 26.6 ± 4.6
Total thyroxine (µg/dL)
Day 4 | 5.52 ± 0.18 | 5.36 ± 0.26 | 4.78 ± 0.34 | 4.87 ± 0.37 | 5.13 ± 0.31 | 4.51 ± 0.35^c^
Day 23 | 5.03 ± 0.26 | 5.44 ± 0.21 | 5.18 ± 0.31 | 5.21 ± 0.24^c^ | 5.68 ± 0.23 | 5.94 ± 0.26
Week 14 | 3.42 ± 0.42^b^ | 3.28 ± 0.23^c^ | 3.84 ± 0.22 | 4.15 ± 0.22 | 3.56 ± 0.21 | 3.48 ± 0.22
Total triiodothyronine (ng/dL)
Day 23 | 147.4 ± 7.3 | 153.9 ± 8.5 | 152.2 ± 6.5 | 158.6 ± 8.6^c^ | 136.7 ± 5.1 | 147.6 ± 5.7
Week 14 | 128.4 ± 4.9 | 107.8 ± 7.1 | 128.8 ± 6.2^b^ | 139.6 ± 7.4 | 115.3 ± 7.7 | 123.2 ± 9.2
Thyroid stimulating hormone (ng/mL)
Day 4 | 7.09 ± 0.25 | 6.77 ± 0.17 | 6.68 ± 0.20 | 6.64 ± 0.12 | 6.60 ± 0.34 | 6.91 ± 0.64^c^
Day 23 | 7.79 ± 0.41 | 7.59 ± 0.31 | 8.13 ± 0.27^b^ | 7.76 ± 0.26^c^ | 7.93 ± 0.24 | 7.55 ± 0.20
Week 14 | 9.46 ± 0.66 | 7.73 ± 0.43 | 8.64 ± 0.35 | 7.41 ± 0.28* | 7.95 ± 0.54 | 7.49 ± 0.21*

* Significantly different (P ≤ 0.05) from the vehicle control group by Dunn’s or Shirley’s test.

** P ≤ 0.01.

^a^ Data are presented as mean ± standard error. Statistical tests were performed on unrounded data.

^b^ n = 9.

^c^ n = 10.

^d^ n = 8.

Table B-2 Hematology Data for Mice in the Three-month Gavage Study of Tetrabromobisphenol A-bis(2,3-dibromopropyl ether)^a^

| Vehicle Control | 125 mg/kg | 250 mg/kg | 500 mg/kg | 1,000 mg/kg | 2,000 mg/kg
Male
n | 10 | 10 | 10 | 9 | 10 | 9
Hematocrit (%) | 51.0 ± 0.6 | 50.2 ± 0.8 | 52.0 ± 1.3 | 50.2 ± 1.0 | 50.9 ± 0.9 | 50.7 ± 0.9
Hemoglobin (g/dL) | 17.4 ± 0.2 | 16.9 ± 0.3 | 17.6 ± 0.5 | 16.9 ± 0.4 | 17.2 ± 0.3 | 17.0 ± 0.3
Erythrocytes (10^6^/µL) | 11.34 ± 0.15 | 11.12 ± 0.15 | 11.59 ± 0.29 | 11.04 ± 0.23 | 11.36 ± 0.20 | 11.26 ± 0.15
Reticulocytes (10^3^/μL) | 278 ± 9 | 300 ± 7 | 304 ± 10 | 294 ± 11 | 298 ± 8 | 286 ± 10
Mean cell volume (fL) | 45.0 ± 0.2 | 45.1 ± 0.2 | 44.9 ± 0.1 | 45.4 ± 0.3 | 44.9 ± 0.2 | 45.0 ± 0.3
Mean cell hemoglobin (pg) | 15.3 ± 0.0 | 15.2 ± 0.1 | 15.2 ± 0.1 | 15.3 ± 0.1 | 15.2 ± 0.1 | 15.1 ± 0.1
Mean cell hemoglobin concentration (g/dL) | 34.0 ± 0.1 | 33.7 ± 0.1 | 33.8 ± 0.1 | 33.7 ± 0.2 | 33.8 ± 0.1 | 33.6 ± 0.2
Platelets (10^3^/μL) | 747 ± 63 | 837 ± 40 | 742 ± 54 | 888 ± 57 | 826 ± 57 | 812 ± 62
Leukocytes (10^3^/μL) | 3.03 ± 0.22 | 3.88 ± 0.22 | 3.33 ± 0.24 | 4.16 ± 0.47 | 3.97 ± 0.33 | 3.84 ± 0.26
Segmented neutrophils (10^3^/μL) | 0.40 ± 0.04 | 0.50 ± 0.05 | 0.43 ± 0.06 | 0.58 ± 0.10 | 0.55 ± 0.07 | 0.59 ± 0.06
Lymphocytes (10^3^/μL) | 2.50 ± 0.18 | 3.21 ± 0.17 | 2.76 ± 0.19 | 3.36 ± 0.34 | 3.27 ± 0.28 | 3.09 ± 0.22
Monocytes (10^3^/μL) | 0.05 ± 0.01 | 0.06 ± 0.01 | 0.06 ± 0.01 | 0.12 ± 0.03 | 0.07 ± 0.01 | 0.07 ± 0.01
Basophils (10^3^/μL) | 0.005 ± 0.002 | 0.007 ± 0.002 | 0.010 ± 0.003 | 0.009 ± 0.003 | 0.005 ± 0.002 | 0.007 ± 0.002
Eosinophils (10^3^/μL) | 0.07 ± 0.02 | 0.09 ± 0.02 | 0.08 ± 0.01 | 0.09 ± 0.02 | 0.09 ± 0.02 | 0.09 ± 0.02
Female
n | 10 | 10 | 10 | 10 | 10 | 10
Hematocrit (%) | 48.4 ± 0.6 | 48.5 ± 0.8 | 48.4 ± 0.4 | 48.1 ± 1.1 | 48.8 ± 0.8 | 48.6 ± 0.8
Hemoglobin (g/dL) | 16.5 ± 0.3 | 16.5 ± 0.3 | 16.4 ± 0.2 | 16.4 ± 0.4 | 16.6 ± 0.3 | 16.5 ± 0.3
Erythrocytes (10^6^/µL) | 10.83 ± 0.13 | 10.95 ± 0.17 | 10.88 ± 0.10 | 10.87 ± 0.24 | 11.06 ± 0.16 | 10.96 ± 0.18
Reticulocytes (10^3^/μL) | 295 ± 10 | 327 ± 22 | 303 ± 22 | 276 ± 16 | 261 ± 20 | 262 ± 13
Mean cell volume (fL) | 44.7 ± 0.2 | 44.3 ± 0.1 | 44.5 ± 0.1 | 44.2 ± 0.1 | 44.2 ± 0.2 | 44.3 ± 0.1
Mean cell hemoglobin (pg) | 15.2 ± 0.1 | 15.1 ± 0.1 | 15.1 ± 0.1 | 15.1 ± 0.1 | 15.0 ± 0.1 | 15.0 ± 0.1
Mean cell hemoglobin concentration (g/dL) | 34.1 ± 0.2 | 34.1 ± 0.2 | 33.9 ± 0.1 | 34.1 ± 0.1 | 33.9 ± 0.1 | 33.9 ± 0.2
Platelets (10^3^/μL) | 676 ± 61 | 701 ± 67 | 729 ± 35 | 698 ± 55 | 811 ± 82 | 773 ± 61
Leukocytes (10^3^/μL) | 3.24 ± 0.31 | 3.51 ± 0.20 | 3.13 ± 0.25 | 3.27 ± 0.13 | 3.56 ± 0.23 | 3.76 ± 0.20
Segmented neutrophils (10^3^/μL) | 0.28 ± 0.03 | 0.29 ± 0.04 | 0.25 ± 0.05 | 0.34 ± 0.07 | 0.40 ± 0.03 | 0.41 ± 0.03*
Lymphocytes (10^3^/μL) | 2.84 ± 0.28 | 3.05 ± 0.19 | 2.71 ± 0.20 | 2.80 ± 0.09 | 2.98 ± 0.19 | 3.20 ± 0.17
Monocytes (10^3^/μL) | 0.06 ± 0.01 | 0.07 ± 0.01 | 0.06 ± 0.01 | 0.06 ± 0.01 | 0.08 ± 0.01 | 0.08 ± 0.01
Basophils (10^3^/µL) | 0.005 ± 0.002 | 0.011 ± 0.003 | 0.004 ± 0.002 | 0.002 ± 0.001 | 0.009 ± 0.002 | 0.009 ± 0.002
Eosinophils (10^3^/μL) | 0.05 ± 0.02 | 0.08 ± 0.02 | 0.06 ± 0.02 | 0.06 ± 0.02 | 0.10 ± 0.02 | 0.06 ± 0.01

* Significantly different (P ≤ 0.05) from the vehicle control group by Shirley’s test.

^a^ Data are presented as mean ± standard error. Statistical tests were performed on unrounded data.