# Appendix A Summary of Nonneoplastic Lesions in Rats and Mice

Table A-1 Summary of the Incidence of Nonneoplastic Lesions in Male Rats in the Three-month Gavage Study of Tetrabromobisphenol A-bis(2,3-dibromopropyl ether)^a^

| Vehicle Control | 62.5 mg/kg | 125 mg/kg | 250 mg/kg | 500 mg/kg | 1,000 mg/kg
Disposition Summary
Animals initially in study | 10 | 10 | 10 | 10 | 10 | 10
Early deaths^b^
Accidental death | – | 1 | – | – | – | –
Natural death | – | 1 | – | – | – | –
Survivors
Terminal euthanasia | 10 | 8 | 10 | 10 | 10 | 10
Animals examined microscopically | 10 | 10 | 10 | 10 | 10 | 10
Alimentary System
Esophagus | (10) | (2) | (0) | (0) | (0) | (10)
Intestine large, cecum | (10) | (1) | (0) | (0) | (0) | (10)
Intestine large, colon | (10) | (2) | (0) | (0) | (0) | (10)
Serosa, parasite metazoan | – | – | – | – | – | 1 (10%)
Intestine large, rectum | (10) | (2) | (0) | (0) | (0) | (10)
Parasite metazoan | – | – | – | – | – | 2 (20%)
Intestine small, duodenum | (10) | (1) | (0) | (0) | (0) | (10)
Intestine small, ileum | (10) | (1) | (0) | (0) | (0) | (10)
Intestine small, jejunum | (10) | (1) | (0) | (0) | (0) | (10)
Liver | (10) | (10) | (10) | (10) | (10) | (10)
Inflammation, chronic | 10 (100%) | 10 (100%) | 10 (100%) | 10 (100%) | 10 (100%) | 10 (100%)
Vacuolization cytoplasmic | 10 (100%) | 10 (100%) | 10 (100%) | 10 (100%) | 10 (100%) | 10 (100%)
Mesentery | (0) | (0) | (0) | (0) | (0) | (1)
Fat, necrosis | – | – | – | – | – | 1 (100%)
Oral mucosa | (0) | (0) | (0) | (0) | (1) | (0)
Cyst, focal | – | – | – | – | 1 (100%) | –
Pancreas | (10) | (2) | (0) | (0) | (0) | (10)
Infiltration cellular, mononuclear cell | 1 (10%) | – | – | – | – | –
Acinus, atrophy | 2 (20%) | – | – | – | – | 1 (10%)
Arteriole, inflammation | 1 (10%) | – | – | – | – | –
Salivary glands | (10) | (2) | (0) | (0) | (0) | (10)
Stomach, forestomach | (10) | (2) | (0) | (0) | (0) | (10)
Stomach, glandular | (10) | (2) | (0) | (0) | (0) | (10)
Muscularis, mineralization | – | – | – | – | – | 1 (10%)
Cardiovascular System
Blood vessel | (10) | (2) | (0) | (0) | (0) | (10)
Heart | (10) | (2) | (0) | (0) | (0) | (10)
Cardiomyopathy | 10 (100%) | 2 (100%) | – | – | – | 10 (100%)
Infiltration cellular, mixed cell | 1 (10%) | – | – | – | – | –
Pigmentation | 1 (10%) | – | – | – | – | –
Endocrine System
Adrenal cortex | (10) | (2) | (0) | (0) | (0) | (10)
Adrenal medulla | (10) | (2) | (0) | (0) | (0) | (10)
Islets, pancreatic | (10) | (2) | (0) | (0) | (0) | (10)
Parathyroid gland | (7) | (2) | (0) | (0) | (0) | (10)
Pituitary gland | (10) | (2) | (0) | (0) | (0) | (10)
Thyroid gland | (10) | (2) | (0) | (0) | (0) | (10)
General Body System
None | – | – | – | – | – | –
Genital System
Epididymis | (10) | (2) | (0) | (0) | (0) | (10)
Inflammation, chronic active | 5 (50%) | – | – | – | – | –
Preputial gland | (10) | (2) | (0) | (0) | (0) | (10)
Inflammation | 3 (30%) | – | – | – | – | 3 (30%)
Prostate | (10) | (2) | (0) | (0) | (0) | (10)
Inflammation, chronic active | 1 (10%) | – | – | – | – | –
Seminal vesicle | (10) | (2) | (0) | (0) | (0) | (10)
Testes | (10) | (2) | (0) | (0) | (0) | (10)
Hematopoietic System
Bone marrow | (10) | (2) | (0) | (0) | (0) | (10)
Lymph node, mandibular | (10) | (2) | (0) | (0) | (0) | (10)
Lymph node, mesenteric | (10) | (9) | (10) | (10) | (10) | (10)
Infiltration cellular, histiocyte | 10 (100%) | 9 (100%) | 10 (100%) | 10 (100%) | 1 (100%) | 10 (100%)
Spleen | (10) | (2) | (0) | (0) | (0) | (10)
Thymus | (10) | (2) | (0) | (0) | (0) | (10)
Integumentary System
Mammary gland | (10) | (2) | (0) | (0) | (0) | (10)
Skin | (10) | (2) | (0) | (0) | (0) | (10)
Musculoskeletal System
Bone | (10) | (2) | (0) | (0) | (0) | (10)
Nervous System
Brain | (10) | (2) | (0) | (0) | (0) | (10)
Respiratory System
Lung | (10) | (10) | (10) | (10) | (10) | (10)
Infiltration cellular, histiocyte | 1 (10%) | 1 (10%) | – | – | 1 (10%) | 1 (10%)
Inflammation, granulomatous | – | 4 (40%) | 8 (80%) | 8 (80%) | 6 (60%) | 2 (20%)
Inflammation, acute | – | 2 (20%) | – | – | – | –
Inflammation, chronic active | 7 (70%) | 1 (10%) | 9 (100%) | 6 (60%) | 8 (80%) | 7 (70%)
Metaplasia, osseous | 1 (10%) | 2 (20%) | – | – | – | –
Nose | (10) | (2) | (0) | (0) | (0) | (10)
Inflammation, chronic active | – | – | – | – | – | 1 (10%)
Trachea | (10) | (2) | (0) | (0) | (0) | (10)
Infiltration cellular, mononuclear cell | 1 (10%) | – | – | – | – | 2 (20%)
Special Senses System
Eye | (10) | (3) | (0) | (0) | (0) | (10)
Harderian gland | (10) | (2) | (0) | (0) | (0) | (10)
Infiltration cellular, mononuclear cell | 2 (20%) | – | – | – | – | –
Inflammation, chronic active | – | – | – | – | – | 1 (10%)
Bilateral, inflammation, chronic active | – | – | – | – | – | 1 (10%)
Urinary System
Kidney | (10) | (2) | (0) | (0) | (0) | (10)
Infiltration cellular, mononuclear cell | 1 (10%) | – | – | – | – | 2 (20%)
Mineralization | 8 (80%) | 1 (50%) | – | – | – | 6 (60%)
Nephropathy | 10 (100%) | 1 (50%) | – | – | – | 10 (100%)
Urinary bladder | (10) | (2) | (0) | (0) | (0) | (10)
Inflammation, chronic | – | – | – | – | – | 1 (10%)
Muscularis, mineralization | – | – | – | – | – | 1 (10%)

^a^ Number of animals examined microscopically at the site and the number of animals with lesion.

^b^ One 62.5 mg/kg rat died a natural death on test day 37 and another 62.5 mg/kg rat died from a dosing accident on day 40; these early death animals were examined for histopathologic lesions.

Table A-2 Summary of the Incidence of Nonneoplastic Lesions in Female Rats in the Three-month Gavage Study of Tetrabromobisphenol A-bis(2,3-dibromopropyl ether)^a^

| Vehicle Control | 62.5 mg/kg | 125 mg/kg | 250 mg/kg | 500 mg/kg | 1,000 mg/kg
Disposition Summary
Animals initially in study | 10 | 10 | 10 | 10 | 10 | 10
Early death
Natural death | 1 | – | – | – | – | –
Survivors
Terminal euthanasia | 9 | 10 | 10 | 10 | 10 | 10
Animals examined microscopically | 10 | 10 | 10 | 10 | 10 | 10
Alimentary System
Esophagus | (10) | (0) | (0) | (0) | (0) | (10)
Intestine large, cecum | (10) | (0) | (0) | (0) | (0) | (10)
Intestine large, colon | (10) | (0) | (0) | (0) | (0) | (10)
Intestine large, rectum | (10) | (0) | (0) | (0) | (0) | (10)
Parasite metazoan | – | – | – | – | – | 1 (10%)
Intestine small, duodenum | (10) | (0) | (0) | (0) | (0) | (10)
Intestine small, ileum | (10) | (0) | (0) | (0) | (0) | (10)
Intestine small, jejunum | (10) | (0) | (0) | (0) | (0) | (10)
Liver | (10) | (8) | (8) | (9) | (10) | (10)
Inflammation, chronic | 8 (80%) | 8 (100%) | 8 (100%) | 9 (100%) | 10 (100%) | 10 (100%)
Pancreas | (10) | (0) | (0) | (0) | (0) | (10)
Salivary glands | (10) | (0) | (0) | (0) | (0) | (10)
Stomach, forestomach | (10) | (0) | (0) | (0) | (0) | (10)
Stomach, glandular | (10) | (0) | (0) | (0) | (0) | (10)
Cardiovascular System
Blood vessel | (10) | (0) | (0) | (0) | (0) | (10)
Heart | (10) | (0) | (0) | (0) | (0) | (10)
Cardiomyopathy | 9 (90%) | – | – | – | – | 9 (90%)
Inflammation, chronic active | 1 (10%) | – | – | – | – | –
Endocrine System
Adrenal cortex | (10) | (0) | (0) | (0) | (0) | (10)
Adrenal medulla | (10) | (0) | (0) | (0) | (0) | (10)
Islets, pancreatic | (10) | (0) | (0) | (0) | (0) | (10)
Parathyroid gland | (10) | (0) | (0) | (0) | (0) | (10)
Pituitary gland | (10) | (0) | (0) | (0) | (0) | (10)
Cyst | – | – | – | – | – | 1 (10%)
Thyroid gland | (10) | (0) | (0) | (0) | (0) | (10)
General Body System
None | – | – | – | – | – | –
Genital System
Clitoral gland | (10) | (0) | (0) | (0) | (0) | (10)
Inflammation, chronic active | 3 (30%) | – | – | – | – | –
Ovary | (10) | (0) | (1) | (0) | (0) | (10)
Left, cyst | – | – | 1 (100%) | – | – | –
Uterus | (10) | (0) | (0) | (0) | (0) | (10)
Hematopoietic System
Bone marrow | (10) | (0) | (0) | (0) | (0) | (10)
Lymph node, mandibular | (10) | (0) | (0) | (0) | (0) | (10)
Lymph node, mesenteric | (10) | (10) | (10) | (10) | (10) | (10)
Infiltration cellular, histiocyte | 10 (100%) | 10 (100%) | 10 (100%) | 10 (100%) | 10 (100%) | 10 (100%)
Spleen | (10) | (0) | (0) | (0) | (0) | (10)
Lymphoid follicle, depletion cellular | 1 (10%) | – | – | – | – | –
Thymus | (10) | (0) | (0) | (0) | (0) | (10)
Integumentary System
Mammary gland | (10) | (0) | (0) | (0) | (0) | (10)
Skin | (10) | (0) | (0) | (0) | (0) | (10)
Musculoskeletal System
Bone | (10) | (0) | (0) | (0) | (0) | (10)
Nervous System
Brain | (10) | (0) | (0) | (0) | (0) | (10)
Respiratory System
Lung | (10) | (10) | (10) | (10) | (10) | (10)
Infiltration cellular, histiocyte | 2 (20%) | 1 (10%) | 2 (20%) | 2 (20%) | – | –
Inflammation, granulomatous | – | 3 (30%) | 6 (60%) | 6 (60%) | 6 (60%) | 5 (50%)
Inflammation, acute | 1 (10%) | – | – | – | – | –
Inflammation, chronic active | 1 (10%) | 4 (40%) | 3 (30%) | 6 (60%) | 6 (60%) | 8 (80%)
Metaplasia, osseous | – | – | – | 1 (10%) | – | –
Bronchiole, metaplasia, squamous | – | – | – | – | – | 1 (10%)
Nose | (10) | (0) | (0) | (0) | (0) | (10)
Squamous epithelium, hyperplasia | – | – | – | – | – | 1 (10%)
Trachea | (10) | (0) | (0) | (0) | (0) | (10)
Infiltration cellular, mononuclear cell | 5 (50%) | – | – | – | – | 4 (40%)
Special Senses System
Eye | (10) | (0) | (0) | (0) | (0) | (10)
Harderian gland | (10) | (0) | (0) | (0) | (0) | (10)
Infiltration cellular, mononuclear cell | 1 (10%) | – | – | – | – | –
Inflammation, chronic active | 2 (20%) | – | – | – | – | 3 (30%)
Bilateral, infiltration cellular, mononuclear cell | – | – | – | – | – | 1 (10%)
Bilateral, inflammation, chronic active | 1 (10%) | – | – | – | – | –
Urinary System
Kidney | (10) | (0) | (0) | (0) | (0) | (10)
Infiltration cellular, mononuclear cell | – | – | – | – | – | 1 (10%)
Mineralization | 7 (70%) | – | – | – | – | 5 (50%)
Nephropathy | 2 (20%) | – | – | – | – | 1 (10%)
Urinary bladder | (10) | (0) | (0) | (0) | (0) | (10)

^a^ Number of animals examined microscopically at the site and the number of animals with lesion.

Table A-3 Summary of the Incidence of Nonneoplastic Lesions in Male Mice in the Three-month Gavage Study of Tetrabromobisphenol A-bis(2,3-dibromopropyl ether)^a^

| Vehicle Control | 125 mg/kg | 250 mg/kg | 500 mg/kg | 1,000 mg/kg | 2,000 mg/kg
Disposition Summary
Animals initially in study | 10 | 10 | 10 | 10 | 10 | 10
Survivors
Terminal euthanasia | 10 | 10 | 10 | 10 | 10 | 10
Animals examined microscopically | 10 | 0 | 0 | 0 | 0 | 10
Alimentary System
Esophagus | (10) | (0) | (0) | (0) | (0) | (10)
Infiltration cellular, mononuclear cell | – | – | – | – | – | 1 (10%)
Liver | (10) | (0) | (0) | (0) | (0) | (10)
Infiltration cellular, mononuclear cell | 3 (30%) | – | – | – | – | 4 (40%)
Pancreas | (10) | (0) | (0) | (0) | (0) | (10)
Inflammation, chronic active | – | – | – | – | – | 1 (10%)
Cardiovascular System
None | – | – | – | – | – | –
Endocrine System
None | – | – | – | – | – | –
General Body System
None | – | – | – | – | – | –
Genital System
Prostate | (10) | (0) | (0) | (0) | (0) | (10)
Infiltration cellular, mononuclear cell | 4 (40%) | – | – | – | – | 4 (40%)
Epithelium, hyperplasia | 1 (10%) | – | – | – | – | –
Hematopoietic System
None | – | – | – | – | – | –
Integumentary System
None | – | – | – | – | – | –
Musculoskeletal System
None | – | – | – | – | – | –
Nervous System
None | – | – | – | – | – | –
Respiratory System
Lung | (10) | (0) | (0) | (0) | (0) | (10)
Alveolus, infiltration cellular, mononuclear cell | – | – | – | – | – | 1 (10%)
Special Senses System
None | – | – | – | – | – | –
Urinary System
Kidney | (10) | (0) | (0) | (0) | (0) | (10)
Infiltration cellular, mononuclear cell | 3 (30%) | – | – | – | – | 3 (30%)
Nephropathy | – | – | – | – | – | 1 (10%)

^a^ Number of animals examined microscopically at the site and the number of animals with lesion.

Table A-4 Summary of the Incidence of Nonneoplastic Lesions in Female Mice in the Three-month Gavage Study of Tetrabromobisphenol A-bis(2,3-dibromopropyl ether)^a^

| Vehicle Control | 125 mg/kg | 250 mg/kg | 500 mg/kg | 1,000 mg/kg | 2,000 mg/kg
Disposition Summary
Animals initially in study | 10 | 10 | 10 | 10 | 10 | 10
Survivors
Terminal euthanasia | 10 | 10 | 10 | 10 | 10 | 10
Animals examined microscopically | 10 | 0 | 0 | 0 | 0 | 10
Alimentary System
Liver | (10) | (0) | (0) | (0) | (0) | (10)
Infiltration cellular, mononuclear cell | 9 (90%) | – | – | – | – | 10 (100%)
Cardiovascular System
None | – | – | – | – | – | –
Endocrine System
None | – | – | – | – | – | –
General Body System
None | – | – | – | – | – | –
Genital System
None | – | – | – | – | – | –
Hematopoietic System
None | – | – | – | – | – | –
Integumentary System
None | – | – | – | – | – | –
Musculoskeletal System
None | – | – | – | – | – | –
Nervous System
None | – | – | – | – | – | –
Respiratory System
Lung | (10) | (0) | (0) | (0) | (0) | (10)
Inflammation, chronic | 1 (10%) | – | – | – | – | –
Special Senses System
None | – | – | – | – | – | –
Urinary System
Kidney | (10) | (0) | (0) | (0) | (0) | (10)
Casts protein | 1 (10%) | – | – | – | – | –
Infiltration cellular, mononuclear cell | 4 (40%) | – | – | – | – | 7 (70%)
Mineralization | – | – | – | – | – | 1 (10%)
Nephropathy | 1 (10%) | – | – | – | – | –

^a^ Number of animals examined microscopically at the site and the number of animals with lesion.