# Peer Review

The draft NTP Technical Report on the Toxicity Studies of o-Phthalaldehyde (CASRN 643-79-8) Administered by Inhalation to Sprague Dawley (Hsd:Sprague^®^ Dawley SD^®^) Rats and B6C3F1/N Mice was evaluated by the reviewers listed below. These reviewers served as independent scientists, not as representatives of any institution, company, or governmental agency. In this capacity, reviewers determined if the design and conditions of these NTP studies were appropriate and ensured that this Toxicity Study Report presented the experimental results and conclusions fully and clearly.

## Peer Reviewers

- Melanie L. Doyle-Eisele, Ph.D.
  Lovelace Respiratory Research Institute
  Albuquerque, New Mexico, USA
- Devon K. Andres, Ph.D.
  The Tauri Group
  Alexandria, Virginia, USA