# Collaborators

- Division of the National Toxicology Program, National Institute of Environmental Health Sciences, Research Triangle Park, North Carolina, USA
  Evaluated and interpreted results and reported findings
  N.R. Catlin, Ph.D., Study Scientist
  C.R. Blystone, Ph.D.
  M.C. Cora, D.V.M.
  P.M. Foster, Ph.D.
  R.A. Herbert, D.V.M., Ph.D.
  M.J. Hooth, Ph.D.
  A.P. King-Herbert, D.V.M.
  G.E. Kissling, Ph.D.
  D.E. Malarkey, D.V.M., Ph.D.
  B.S. McIntyre, Ph.D.
  M.D. Stout, Ph.D.
  S.A. Thakur, Ph.D.
  G.S. Travlos, D.V.M.
  M.K. Vallant, M.T.
  S. Waidyanatha, Ph.D.
  N.J. Walker, Ph.D.
  K.L. Witt, M.S.
  M.E. Wyde, Ph.D.
- ILS, Inc., Research Triangle Park, North Carolina, USA
  Evaluated and interpreted results and reported findings
  C.J. Willson, D.V.M., Ph.D., Study Pathologist
  A. Nyska, D.V.M.
  D.B. Rao, Ph.D.
- Battelle Toxicology Northwest, Richland, Washington, USA
  Conducted studies and evaluated pathology findings
  J.A. Dill, Ph.D., Principal Investigator
  S.L. Grumbein, D.V.M., Ph.D.
  B.K. Hayden
  L.M. Staska, D.V.M., Ph.D.
- Experimental Pathology Laboratories, Inc., Research Triangle Park, North Carolina, USA
  Conducted pathology review
  T.A. Crabbs, D.V.M.
- Pathology Associates, A Division of Charles River Laboratories, Inc., Research Triangle Park, North Carolina, USA
  Coordinated NTP Pathology Working Group (May 3 and 5, 2011)
  C.L. Johnson, D.V.M
- RTI International, Research Triangle Park, North Carolina, USA
  Provided sperm parameter analysis
  R.W. Tyl, Ph.D., Principal Investigator
  C.S. Sloan, M.S.