# References

1 Dynamac Corporation. o-Phthalaldehyde. Task 5: Product chemistry support registration division. Rockville, MD: Submitted to the U.S. Environmental Protection Agency by Dynamac Corporation; 1990. Contract No. 68-D8-0080.
2 Aldrich Chemical Company The 2000-2001 Aldrich Handbook of Fine Chemicals and Laboratory Equipment. Milwaukee (WI): Aldrich Chemical Company; 2000. 1,2 Benzenedicarboxaldehyde.
3 Chaudhuri T A new synthesis of phthalaldehydes. J Am Chem Soc. 1942;64:315. http://dx.doi.org/10.1021/ja01254a029
4 Sajtos A. inventor. Process for preparation of monocarbonyl or bicarbonyl compounds. United States patent 4769464; September 6, 1988.
5 Ishii Y, Nakano T. inventors. Method for production of aldehydes. United States patent 6201156; March 13, 2001.
6 Yoshinaka S, Doya M. inventors. Process for the production of aromatic aldehydes. United States patent 4328374; May 4, 1982.
7 Nakai T. inventor. Process for producing phthalaldehyde. United States patent 6797844; September 28, 2004.
8 Degner D. inventor. Preparation of phthalaldehyde acetals. United States patent 4588482; May 13, 1986.
9 Giselbrecht K, Reiter K, Perndorfer E, Hermanseder R. inventors. Process for the purification of o-phthalaldehyd. United States patent 5874637; February 23, 1999.
10 Rutala WA Weber DJ New disinfection and sterilization methods. Emerg Infect Dis. 2001;7(2):348–353. http://dx.doi.org/10.3201/eid0702.010241 11294738
11 Akamatsu T Minemoto M Uyeda M Evaluation of the antimicrobial activity and materials compatibility of orthophthalaldehyde as a high-level disinfectant. J Int Med Res. 2005;33(2):178–187. http://dx.doi.org/10.1177/147323000503300205 15790129
12 U.S. Environmental Protection Agency (USEPA). 1,2-Benzenedicarboxaldehyde. U.S. Environmental Protection Agency, Office of Pesticide Programs; 2016. https://iaspub.epa.gov/apex/pesticides/f?p=CHEMICALSEARCH:3:::NO:1,3,31,7,12,25:P3_XCHEMICAL_ID:94
13 Marena C Lodola L Marone Bianco A Maestri L Alessio A Negri S Zambianchi L [Monitoring air dispersed concentrations of aldehydes during the use of ortho-phthalaldehyde and glutaraldehyde for high disinfection of endoscopes] [in Italian, English summary]. G Ital Med Lav Ergon. 2003;25(2):131–136. 12872495
14 Tucker SP Determination of ortho-phthalaldehyde in air and on surfaces. J Environ Monit. 2008;10(11):1337–1349. http://dx.doi.org/10.1039/b809790a 18974903
15 National Institute for Occupational Safety and Health (NIOSH). National Occupational Exposure Survey (1981-1983) [unpublished provisional data]. Cincinnati, OH. 1990.
16 Chen L, Eisenberg J, Mueller C, Burton N. Evaluation of ortho-phthalaldehyde in eight healthcare facilities. Cincinnati, OH: U.S. Department of Health and Human Services, Centers for Disease Control and Prevention, National Institute for Occupational Safety and Health; 2015. Health Hazard Evaluation Report No. 2006-0238-3239.
17 Food and Drug Administration (FDA). FDA-Cleared sterilants and high level disinfectants with general claims for processing reusable medical and dental devices - March 2015. 2016. https://www.fda.gov/MedicalDevices/DeviceRegulationandGuidance/ReprocessingofReusableMedicalDevices/ucm437347.htm [Accessed: June 1, 2016]
18 Centers for Disease Control and Prevention (CDC) NIOSH Pocket Guide to Chemical Hazards. Cincinnati (OH): Department of Health and Human Services, Centers for Disease Control and Prevention, National Institute for Occupational Safety and Health; 2016. Glutaraldehyde.
19 Ohtawa M Ichimoto S Nakaki R Sugimoto K Absorption and excretion of [14C] ortho-phthalaldehyde following intratracheal and oral administration to male rat. Jpn Pharmacol Ther. 2001;29(9):611–622.
20 Products AS. (ASP). Material Safety Data Sheet (MSDS): CIDEX® OPA Solution. Irvine, CA: Advanced Sterilization Products (ASP); 2005. MSDS No. 09588-0-001.
21 Auriac P Caujolle F Frajdenrach S Meynier D Troplent L [Toxicity of phthalic aldehydes]. C R Hebd Seances Acad Sci. 1956;243(23):1933–1934. 13397028
22 Hasegawa G Morinaga T Ishihara Y ortho-Phthalaldehyde enhances allergen-specific IgE production without allergen-specific IgG in ovalbumin-sensitized mice. Toxicol Lett. 2009;185(1):45–50. http://dx.doi.org/10.1016/j.toxlet.2008.11.016 19110043
23 Morinaga T Hasegawa G Koyama S Ishihara Y Nishikawa T Acute inflammation and immunoresponses induced by ortho-phthalaldehyde in mice. Arch Toxicol. 2010;84(5):397–404. http://dx.doi.org/10.1007/s00204-010-0512-1 20112102
24 Anderson SE Umbright C Sellamuthu R Fluharty K Kashon M Franko J Jackson LG Johnson VJ Joseph P Irritancy and allergic responses induced by topical application of ortho-phthalaldehyde. Toxicol Sci. 2010;115(2):435–443. http://dx.doi.org/10.1093/toxsci/kfq054 20176622
25 Fujita H Ogawa M Endo Y A case of occupational bronchial asthma and contact dermatitis caused by ortho-phthalaldehyde exposure in a medical worker. [in Japanese, English summary]. J Occup Health. 2006;48(6):413–416. http://dx.doi.org/10.1539/joh.48.413 17179633
26 Johnson VJ Reynolds JS Wang W Fluharty K Yucesoy B Inhalation of ortho-phthalaldehyde vapor causes respiratory sensitization in mice. J Allergy (Cairo). 2011;2011:751052. http://dx.doi.org/10.1155/2011/751052 21785612
27 Katagiri H Yamamoto T Uchimura A Tsunoda M Aizawa Y Yamauchi H The alterations in neurotransmitters and their metabolites in discrete brain regions in the rats after inhalation of disinfectant, glutaraldehyde or ortho-phthalaldehyde for 4 weeks. Ind Health. 2011;49(3):328–337. http://dx.doi.org/10.2486/indhealth.MS1156 21372440
28 Streckenbach SC Alston TA Perioral stains after ortho-phthalaldehyde disinfection of echo probes. Anesthesiology. 2003;99(4):1032. http://dx.doi.org/10.1097/00000542-200310000-00049 14508346
29 Venticinque SG Kashyap VS O’Connell RJ Chemical burn injury secondary to intraoperative transesophageal echocardiography. Anesth Analg. 2003;97(5):1260–1261. http://dx.doi.org/10.1213/01.ANE.0000083641.58267.0C 14570634
30 Sokol WN Nine episodes of anaphylaxis following cystoscopy caused by Cidex OPA (ortho-phthalaldehyde) high-level disinfectant in 4 patients after cytoscopy. J Allergy Clin Immunol. 2004;114(2):392–397. http://dx.doi.org/10.1016/j.jaci.2004.04.031 15316522
31 Suzukawa M Komiya A Koketsu R Kawakami A Kimura M Nito T Yamamoto K Yamaguchi M Three cases of ortho-phthalaldehyde-induced anaphylaxis after laryngoscopy: detection of specific IgE in serum. Allergol Int. 2007;56(3):313–316. http://dx.doi.org/10.2332/allergolint.C-06-51 17582212
32 Franchi A Franco G Evidence-based decision making in an endoscopy nurse with respiratory symptoms exposed to the new ortho-phthalaldehyde (OPA) disinfectant. Occup Med (Lond). 2005;55(7):575–578. http://dx.doi.org/10.1093/occmed/kqi119 16251378
33 Miyajima K Yoshida J Kumagai S Ortho-phthalaldehyde exposure levels among endoscope disinfection workers. Sangyo Eiseigaku Zasshi. 2010;52(2):74. http://dx.doi.org/10.1539/sangyoeisei.B9013 20160422
34 Fujita H Sawada Y Ogawa M Endo Y Health hazards from exposure to ortho-phthalaldehyde, a disinfectant for endoscopes, and preventive measures for health care workers. J Occup Health. 2007;49(1):1–8. 17314460
35 Abdulla FR Adams BB Ortho-phthalaldehyde causing facial stains after cystoscopy. Arch Dermatol. 2007;143(5):670. http://dx.doi.org/10.1001/archderm.143.5.670-a 17515529
36 Harbell J. CHO/HGPRT mutation assay, with confirmation. Bethesda, MD: Microbiological Associates; 1988. Unpublished Study No. T8241.332001.
37 Weissman SH Beethe RL Redman HC Ammonia concentrations in an animal inhalation exposure chamber. Lab Anim Sci. 1980;30(6):974–980. 7464032
38 Brecher G, Schneiderman M. A time-saving device for the counting of reticulocytes. Am J Clin Pathol. 1950; 20(11_ts):1079-1083. http://dx.doi.org/10.1093/ajcp/20.11_ts.1079
39 Maronpot RR Boorman GA Interpretation of rodent hepatocellular proliferative alterations and hepatocellular tumors in chemical safety assessment. Toxicol Pathol. 1982;10(2):71–78. http://dx.doi.org/10.1177/019262338201000210 28094716
40 Boorman GA Montgomery CA Jr Eustis SL Wolfe MJ McConnell EE Hardisty JF Quality assurance in pathology for rodent carcinogenicity studies. In: Milman HA Weisburger EKeditors. Handbook of Carcinogen Testing. Park Ridge (NJ): Noyes Publications; 1985. p. 345–357.
41 Gart JJ Chu KC Tarone RE Statistical issues in interpretation of chronic bioassay tests for carcinogenicity. J Natl Cancer Inst. 1979;62(4):957–974. 285297
42 Armitage P Statistical methods in medical research. New York (NY): John Wiley and Sons; 1971.
43 Dunnett CW A multiple comparison procedure for comparing several treatments with a control. J Am Stat Assoc. 1955;50(272):1096–1121. http://dx.doi.org/10.1080/01621459.1955.10501294
44 Williams DA A test for differences between treatment means when several dose levels are compared with a zero dose control. Biometrics. 1971;27(1):103–117. http://dx.doi.org/10.2307/2528930 5547548
45 Williams DA The comparison of several dose levels with a zero dose control. Biometrics. 1972;28(2):519–531. http://dx.doi.org/10.2307/2556164 5037867
46 Shirley E A non-parametric equivalent of Williams’ test for contrasting increasing dose levels of a treatment. Biometrics. 1977;33(2):386–389. http://dx.doi.org/10.2307/2529789 884197
47 Williams DA A note on Shirley’s nonparametric test for comparing several dose levels with a zero-dose control. Biometrics. 1986;42(1):183–186. http://dx.doi.org/10.2307/2531254 3719054
48 Dunn OJ Multiple comparisons using rank sums. Technometrics. 1964;6(3):241–252. http://dx.doi.org/10.1080/00401706.1964.10490181
49 Jonckheere A A distribution-free k-sample test against ordered alternatives. Biometrika. 1954;41:133–145. http://dx.doi.org/10.1093/biomet/41.1-2.133
50 Dixon W Massey F Introduction to statistical analysis. New York (NY): McGraw Hill Book Company Inc; 1957. http://dx.doi.org/10.2307/2332898
51 Code of Federal Regulations (CFR). 21:Part 58.
52 Zeiger E Anderson B Haworth S Lawlor T Mortelmans K Salmonella mutagenicity tests: V. Results from the testing of 311 chemicals. Environ Mol Mutagen. 1992;19 Suppl 21:2–141. http://dx.doi.org/10.1002/em.2850190603 1541260
53 Witt KL Livanos E Kissling GE Torous DK Caspary W Tice RR Recio L Comparison of flow cytometry- and microscopy-based methods for measuring micronucleated reticulocyte frequencies in rodents treated with nongenotoxic and genotoxic chemicals. Mutat Res. 2008;649(1-2):101–113. http://dx.doi.org/10.1016/j.mrgentox.2007.08.004 17869571
54 Kissling GE Dertinger SD Hayashi M MacGregor JT Sensitivity of the erythrocyte micronucleus assay: dependence on number of cells scored and inter-animal variability. Mutat Res. 2007;634(1-2):235–240. http://dx.doi.org/10.1016/j.mrgentox.2007.07.010 17851117
55 Picut CA Remick AK de Rijk EP Simons ML Stump DG Parker GA Postnatal development of the testis in the rat: morphologic study and correlation of morphology to neuroendocrine parameters. Toxicol Pathol. 2015;43(3):326–342. http://dx.doi.org/10.1177/0192623314547279 25217330
56 Rudel LL Morris MD Determination of cholesterol using o-phthalaldehyde. J Lipid Res. 1973;14(3):364–366. 14580182
57 Lenton KJ Therriault H Wagner JR Analysis of glutathione and glutathione disulfide in whole cells and mitochondria by postcolumn derivatization high-performance liquid chromatography with ortho-phthalaldehyde. Anal Biochem. 1999;274(1):125–130. http://dx.doi.org/10.1006/abio.1999.4258 10527505
58 Senft AP Dalton TP Shertzer HG Determining glutathione and glutathione disulfide using the fluorescence probe o-phthalaldehyde. Anal Biochem. 2000;280(1):80–86. http://dx.doi.org/10.1006/abio.2000.4498 10805524
59 U.S. Environmental Protection Agency (USEPA). Method 531.2: Measurement of N-methylcarbamoyloximes and N-methylcarbamates in water by direct aqueous injection HPLC with postcolumn derivatization. Cincinnati, OH: US Environmental Protection Agency, Office of Ground Water and Drinking Water; 2001. EPA-815-B-01-002.
60 National Toxicology Program (NTP). Toxicity studies of glutaraldehyde (CAS No. 111-30-8) administered by inhalation to F344/N rats and B6C3F1 mice. Research Triangle Park, NC: U.S. Department of Health and Human Services, Public Health Service, National Institutes of Health; 1993. Toxicity Report Series No. 25. NIH Publication No. 93-3348.
61 National Toxicology Program (NTP). Toxicity studies of triethylamine (CAS No. 121-44-8) administered by inhalation to F344/N rats and B6C3F1/N mice. Research Triangle Park, NC: U.S. Department of Health and Human Services, Public Health Service, National Institutes of Health; 2017. Toxicity Report Series No. 78.
62 National Toxicology Program (NTP). Toxicology and carcinogenesis studies of diethylamine (CAS No. 109-89-7) in F344/N rats and B6C3F1 mice (inhalation studies). Research Triangle Park, NC: U.S. Department of Health and Human Services, Public Health Service, National Institutes of Health; 2011. Technical Report Series No. 566. NIH Publication No. 12-5908.
63 Kruysse A Feron VJ Til HP Repeated exposure to acetaldehyde vapor. Studies in Syrian golden hamsters. Arch Environ Health. 1975;30(9):449–452. http://dx.doi.org/10.1080/00039896.1975.10666748 1164047
64 National Toxicology Program (NTP). Toxicology and carcinogenesis studies of glutaraldehyde (CAS No. 111-30-8) in F344/N rats and B6C3F1 mice (inhalation studies). Research Triangle Park, NC: U.S. Department of Health and Human Services, Public Health Service, National Institutes of Health; 1999. Technical Report Series No. 490. NIH Publication No. 99-3980.
65 Boorman GA Morgan K Uriah L Nose, larynx, and trachea. In: Boorman GA Eustis SL Elwell M Montgomery CA Jr MacKenzie Weditors. Pathology of the Fischer Rat: Reference and Atlas. San Diego (CA): Academic Press Inc; 1990. p. 315–337.
66 Renne R, Brix A, Harkema J, Herbert R, Kittel B, Lewis D, March T, Nagano K, Pino M, Rittinghausen S, et al. Proliferative and nonproliferative lesions of the rat and mouse respiratory tract. Toxicol Pathol. 2009; 37(7_suppl):5S-73S. http://dx.doi.org/10.1177/0192623309353423
67 National Cancer Institute (NCI). Bioassay of 3-sulfolene for possible carcinogenicity (CAS No. 77-79-2). Bethesda, MD: U.S. Department of Health, Education, and Welfare, Public Health Service, National Institutes of Health; 1978. Technical Report Series No. 102. NIH Publication No. 78-1352.
68 National Toxicology Program (NTP). Toxicology and carcinogenesis studies of Elmiron® (CAS No. 37319 17-8) in F344/N rats and B6C3F1 mice (gavage studies). Research Triangle Park, NC: U.S. Department of Health and Human Services, Public Health Service, National Institutes of Health; 2004. Technical Report Series No. 512. NIH Publication No. 04-4446.
69 National Toxicology Program (NTP). Toxicology and carcinogenesis studies of ginseng (CAS No. 50647-08-0) in F344/N rats and B6C3F1 mice (gavage studies). Research Triangle Park, NC: U.S. Department of Health and Human Services, Public Health Service, National Institutes of Health; 2011. Technical Report Series No. 567. NIH Publication No. 11-5909.
70 National Cancer Institute (NCI). Bioassay of 1,1,1-trichloroethane for possible carcinogenicity (CAS No. 71-55-6). Bethesda, MD: U.S. Department of Health, Education, and Welfare, Public Health Service, National Institutes of Health; 1977. Technical Report Series No. 3.
71 Barrow C Steinhagen W Chang J Formaldehyde sensory irritation. In: Gibson Jeditor. Formaldehyde Toxicity. Washington (DC): Hemisphere Publishing Corporation; 1983.
72 Cooke RP Goddard SV Whymant-Morris A Sherwood J Chatterly R An evaluation of Cidex OPA (0.55% ortho-phthalaldehyde) as an alternative to 2% glutaraldehyde for high-level disinfection of endoscopes. J Hosp Infect. 2003;54(3):226–231. 10.1016/S0195-6701(03)00040-9 12855240
73 Horikiri M, Park S, Matsui T, Suzuki K, Matsuoka T. Ortho-phthalaldehyde-induced skin mucous membrane damage from inadequate washing. BMJ Case Rep. 2011. http://dx.doi.org/10.1136/bcr.02.2010.2709
74 Everds NE Snyder PW Bailey KL Bolon B Creasy DM Foley GL Rosol TJ Sellers T Interpreting stress responses during routine toxicity studies: a review of the biology, impact, and assessment. Toxicol Pathol. 2013;41(4):560–614. http://dx.doi.org/10.1177/0192623312466452 23475558
75 Richburg JH Johnson KJ Schoenfeld HA Meistrich ML Dix DJ Defining the cellular and molecular mechanisms of toxicant action in the testis. Toxicol Lett. 2002;135(3):167–183. http://dx.doi.org/10.1016/S0378-4274(02)00254-0 12270675
76 Creasy DM Pathogenesis of male reproductive toxicity. Toxicol Pathol. 2001;29(1):64–76. http://dx.doi.org/10.1080/019262301301418865 11215686
77 O’Donnell L McLachlan RI Wreford NG Robertson DM Testosterone promotes the conversion of round spermatids between stages VII and VIII of the rat spermatogenic cycle. Endocrinology. 1994;135(6):2608–2614. http://dx.doi.org/10.1210/endo.135.6.7988449 7988449