# Discussion

o-Phthalaldehyde was introduced to the United States market in 1999 as a safer alternative high-level chemical disinfectant for medical equipment compared to glutaraldehyde. Glutaraldehyde has been used extensively to disinfect heat-sensitive medical equipment such as endoscopes and thermometers, but it has been associated with adverse health outcomes (e.g., dermatitis and occupational asthma).^11^ o-Phthalaldehyde is considered to be safer than glutaraldehyde due to its antimicrobial efficacy combined with its lower vapor pressure.^11,20^ However, the low vapor pressure and low odor of o-phthalaldehyde can present an occupational hazard, because its presence in room air would not be as noticeable to workers. There are limited studies assessing the safety of o-phthalaldehyde; however, dermal sensitization and inhalation studies have found o-phthalaldehyde to be a dermal irritant and contact-sensitizer that can also cause irritation to the eyes and the mucus membranes lining the respiratory tract.^24,26^

There are no existing personal exposure limits or recommended guidelines established by the Occupational Safety and Health Administration (OSHA) or the National Institute for Occupational Safety and Health (NIOSH) for o-phthalaldehyde in occupational settings. Though there is no personal exposure limit established by OSHA or NIOSH for o-phthalaldehyde, glutaraldehyde has a NIOSH Recommended Exposure Limit of 0.2 ppm (0.8 mg/m^3^) and the American Conference of Governmental Industrial Hygienists recommends a Threshold Limit Value of 0.05 ppm in air.^18^ In addition to its widespread occupational use as a disinfectant, o-phthalaldehyde has many other uses that include diagnostic tests,^56-58^ as a reagent in drinking water analysis,^59^ and as an intermediate in pharmaceutical or chemical synthesis. There is potential for occupational exposure in the health care industry during chemical disinfection of medical equipment; o-phthalaldehyde has been detected in air samples from hospital endoscopy units in Italy and the United States at levels ranging from 1.0 to 13.5 ppb.^13,14^ As a result of its increasing use and the lack of adequate and publicly available toxicity data, o-phthalaldehyde was nominated for study by NIOSH for toxicologic characterization. Given the occupational use pattern, whole-body inhalation was chosen as the route of exposure for the current studies.

The exposure concentrations for these 3-month inhalation studies in Sprague Dawley rats and B6C3F1/N mice were 0, 0.44, 0.88, 1.75, 3.5, and 7.0 ppm o-phthalaldehyde. The highest exposure concentration was selected based on NTP evaluations of the maximum achievable concentration without aerosolization under normal chamber environmental specifications. The lowest concentration was similar to the experimental limit of quantitation for the online monitor used in these studies. Although a lower limit of quantitation may have been achievable using this online monitor or available offline methods, exposure of animals to lower concentrations was not feasible under the conditions of these studies, due to reactivity of the aldehyde moieties of o-phthalaldehyde with amines resulting from the presence of animals. In the current studies, the main toxicity targets of o-phthalaldehyde exposure in rats and mice included the respiratory system (nasal cavity, larynx, trachea, lung), other sites of contact (skin, eye), and the male reproductive system (testis, epididymis).

Exposure to o-phthalaldehyde for 3 months caused overt toxicity at the two highest exposure concentrations in rats and mice, resulting in clinical findings of toxicity (e.g., abnormal breathing, sneezing, and thinness) and death. All of the rats and mice exposed to 7.0 ppm o-phthalaldehyde died within the first 2 weeks of study. Among animals that were exposed to 3.5 ppm o-phthalaldehyde, 70% of the male rats and 20% of the female rats died in the first 7 weeks of exposure and 50% of the male mice and 40% of the female mice died by week 6 of exposure. The decreased survival may be attributable to the significant extent of the respiratory lesions. Upon microscopic evaluation, suppurative inflammation in the nose was noted in almost all exposed animals. This finding in rats and mice, which are obligate nose-breathing animals, may have interfered with drinking and eating and may have contributed to respiratory insufficiency, and possibly death.

The most significant toxic response to o-phthalaldehyde inhalation occurred within the respiratory tract, including the nose, larynx, trachea, and lung, of rats and mice. In general, exposure of rats and mice to o-phthalaldehyde resulted in a spectrum of lesions throughout the respiratory tract that included necrosis, inflammation, regeneration, hyperplasia, and metaplasia, ranging from minimal to moderate in severity. In general, histologic findings occurred at deeper sites within the respiratory tract with increasing exposure concentration. The first site of contact, the nose, was most affected, with many lesions occurring at the lowest exposure concentration (0.44 ppm) in male and female rats and mice. Laryngeal lesions occurred at all exposure concentrations in rats and at 0.88 ppm or greater in mice. Tracheal findings were first noted at a variety of exposure concentrations. Lung findings were most prevalent at the two highest exposure concentrations (3.5 and 7.0 ppm) in rats and mice. Knowing the extent of the respiratory tract lesions, the increase in the erythron observed in the rats at study termination may be due, at least in part, to hypoxia with a resultant secondary appropriate erythrocytosis; decreased water intake may also have contributed.

In comparison to a previous study of glutaraldehyde by inhalation for 3 months, respiratory lesions were limited to the anterior region of the nose and did not extend further into the respiratory tract.^60^ The mice in the 3-month glutaraldehyde study had lesions that extended past the nasal cavity and into the larynx, but only at the highest exposure concentration (1 ppm). From the studies with glutaraldehyde, the no-observed-adverse-effect concentration (NOAEC) was determined to be 0.125 ppm in rats and no no-observed-effect concentration (NOEC) was reached for the mice due to the occurrence of inflammation in the anterior nasal passage at the lowest concentration administered (0.0625 ppm).

The nasal cavity was a target of o-phthalaldehyde toxicity in the 3-month studies in both rats and mice. As rodents are obligate nose breathers, the nasal cavity is often a primary target site for direct-acting, reactive, and gaseous chemicals, including triethylamine^61^ and diethylamine^62^ and other aldehydes such as acetaldehyde^63^ and glutaraldehyde.^64^ The nasal epithelium response to toxicant injury often includes the co-occurrence of inflammation, atrophy, degeneration, or necrosis, as well as the reparative or adaptive responses of metaplasia, hyperplasia, or regeneration. Following o-phthalaldehyde inhalation, suppurative inflammation in the nasal cavity was observed in nearly all animals in all exposed groups. Necrosis of the respiratory epithelium occurred in male and female rats and mice, in an exposure concentration-dependent manner with increasing severity; however, this excludes the top two exposure groups (3.5 and 7.0 ppm) in which the animals died early in the study. Sequelae of the necrosis seen in male and female rats and mice in this study include regeneration of the original respiratory epithelium or metaplasia to a different histologic type of epithelium. Squamous metaplasia, observed in this study at increased incidences in either olfactory or respiratory epithelium, is a common adaptive response to prolonged or repeated injury to the epithelium and results in the replacement of injured epithelium with more resistant squamous epithelium.^65^ A spectrum of similar changes was also seen within the olfactory epithelium of both sexes of rats and mice in these studies. Additionally, all exposed male and female rats and mice (except male rats at 7.0 ppm) had significantly increased incidences of olfactory epithelium atrophy, which is a lesion that often occurs subsequent to either degeneration or necrosis.^66^ As is often the case with atrophy of the olfactory epithelium, the underlying turbinate bones may also be atrophic with incidences and severity generally increasing with increasing exposure concentration. The absence of nasal turbinate atrophy in the 7.0 ppm groups of rats and mice and in the 3.5 ppm group of male rats is likely due to decreased exposure time due to early deaths. Similar nasal lesions were seen following a 3-month inhalation exposure to glutaraldehyde and included hyperplasia and squamous metaplasia of the respiratory epithelium lining the nasoturbinates/septum, as well as degeneration of the olfactory epithelium.^60^ However, these lesions were mostly present only at the highest exposure concentration tested (1 ppm) and the extent of the lesions following glutaraldehyde exposure was also much less than that observed in these studies with o-phthalaldehyde. Inhalation exposure to diethylamine induced the same distribution of lesions within the nasal cavity at incidences that were significantly increased following inhalation exposure to 62 or 125 ppm for 3 months.^62^ It would appear from the comparison of these studies that o-phthalaldehyde may not be a safer alternative to glutaraldehyde or diethylamine, with many of the o-phthalaldehyde-induced lesions extending throughout the entire respiratory tract.

o-Phthalaldehyde-induced lesions extended deeper into the respiratory tract, also targeting the larynx, trachea, bronchi, and lung. As in the nasal cavity, many of the lesions increased in incidence and severity with exposure concentration and covered a spectrum of injury as a result of continued o-phthalaldehyde exposure. In the larynx and trachea there were also exposure concentration-dependent increases in the incidences of squamous metaplasia, which was present in both sexes of rats and mice as well. Some of the male and female rats that died early in the high concentration exposure groups (3.5 and 7.0 ppm) had ulceration of the mucosal epithelium in the trachea. Singular incidences of trachea ulcerations have previously been reported in 2-year NTP oral gavage studies in rats with either 3-sulfolene, Elmiron^®^, or ginseng; however, these incidences were not considered test article related.^67-69^ Another NTP study where this lesion was observed was a 2-year oral gavage study with 1,1,1-trichloroethane, in which the male Osborne-Mendel rats exhibited increased incidences of acute ulcers in the trachea (5%, 6%, and 14% at 0, 750, and 1,500 mg 1,1,1-trichloroethane/kg body weight, respectively).^70^ In response to the chronic active inflammation and/or necrosis within the trachea and larynx, there were also concentration-dependent increases in the incidences of regeneration and/or squamous metaplasia in rats and mice.

The lung was also a target of o-phthalaldehyde exposure and exhibited significantly increased incidences of histiocytic or suppurative inflammation of the alveolus in male and female rats. Given the ability of o-phthalaldehyde to induce neutrophil infiltration in the bronchoalveolar fluid in ICR mice following subcutaneous injection^22^ and that o-phthalaldehyde has been identified as an irritant and contact sensitizer,^24^ it is not surprising to see inflammation, either suppurative or chronic active, throughout the respiratory tract. The apparent increased sensitivity of the rats in comparison to the mice with the lesions that extended deeper into the respiratory tract, with the lung in particular, may be due to differences in minute volume (respiratory rate × volume of inhaled air). In response to sensory irritant inhalation, mice have been shown to reduce their minute volume by 75% (in the case of formaldehyde exposure), whereas rats only reduced their minute volume by 45%.^71^ In rats, chronic active inflammation and necrosis in the bronchus at the higher exposure concentrations (1.75 ppm or greater) also occurred in conjunction with regeneration, hyperplasia, and/or squamous metaplasia. In the bronchus in mice, incidences of chronic active inflammation and necrosis were only present at the two highest exposure concentrations (3.5 and 7.0 ppm).

Ocular findings in male and female rats in the current study included significantly increased incidences of necrosis and suppurative inflammation of the cornea, as well as suppurative inflammation within the anterior chamber. Although these lesions are more severe than those found following occupational exposures, the rats were exposed for a longer period of time than humans occupationally exposed, and the significantly increased incidences of these lesions were limited to some rats exposed within the two highest exposure concentrations (3.5 and 7.0 ppm). There were also incidences of these cornea lesions in the mice, and although the increases were not statistically significant, their presence is likely treatment related given the significantly increased incidences in rats. Suppurative inflammation within the eye following whole-body inhalation exposures generally occurs in cases where the epithelium is compromised (e.g., abrasions or toxicant-induced necrosis). Mild to moderate suppurative inflammation of the corneas in male and female rats has previously been reported in NTP studies following a longer 2-year exposure to 125 ppm diethylamine.^62^

In the current studies, treatment-related skin lesions were noted in both rats and mice, and clinical findings of black discoloration of the pinnae and feet were noted in rats during the in-life portion of the study. All the male and female mice in the highest exposure group (7.0 ppm) also had several lesions of the skin of the pinna, which included adnexa degeneration, chronic active inflammation, hair follicle epithelium parakeratosis, and squamous hyperplasia. The pinnae are not typically a protocol-required tissue for evaluation in NTP toxicity studies; however, because lesions in routine inguinal skin sections in rats and mice and discoloration of the appendages in the rats were noted in this study, pinnae were evaluated in mice in addition to the routine inguinal skin sections. The cause of o-phthalaldehyde-induced black discoloration is unknown; however, it has been shown that a condensation reaction occurs in humans between o-phthalaldehyde and ammonia, in the presence of water, resulting in the production of similar discoloration.^72^ Additional dermal findings were identified in rats and mice, which are consistent with a dermal irritation response. Ocular and dermal effects, including eye irritation and contact dermatitis, have been documented in workers exposed to o-phthalaldehyde.^25,32-34^ There have also been specific isolated human case reports of skin damage and discoloration in response to o-phthalaldehyde residues on medical equipment following disinfection.^35,73^

Significantly increased incidences of lymphoid atrophy occurred in the thymus and spleen in both male and female rats and mice, and were limited to the top two exposure groups (3.5 and 7.0 ppm). The lymphoid atrophy in the thymus and spleen observed in the current studies is consistent with stress-related organ effects that are a common secondary finding in toxicity studies. The thymus is one of the most sensitive lymphoid organs to stress in toxicity studies.^74^ Further support of stress within this study included the decreased body weights and the clinical findings of thinness. In addition, alterations observed in the leukon on days 3 and 23 and at week 14 (namely decreased lymphocyte counts) were also consistent with a stress response.

In mice, bone marrow hyperplasia was observed at the three highest exposure concentrations (1.75, 3.5, and 7.0 ppm) in the males and only at 3.5 ppm in females. The bone marrow hyperplasia, with subjectively observed increases in the myeloid series (i.e., increased myeloid:erythroid ratio), is most likely due to an increased peripheral demand for leukocytes paired with an erythroid suppression (as indicated by the decreases in the erythron) due to the chronic inflammation. The increased peripheral demand for leukocytes likely stems from the inflammation in the respiratory tract and parallels the increases in the leukocyte counts observed in all exposed male groups and in the 3.5 ppm females.

Microscopic findings consistent with peripuberty were noted in the testis and epididymis of male rats exposed to the two highest exposure concentrations (3.5 and 7.0 ppm) that died early within the first 2 weeks, but not in male mice, as mice reach sexual maturity earlier than rats. In the o-phthalaldehyde-exposed rats, some of the testicular microscopic observations (e.g., low numbers of elongated spermatids, relatively small testicular size and tubule lumen diameters as compared to adults, no or negligible sperm in the epididymis) were consistent with those that were found in the age-matched controls, and therefore these effects in the rat were attributed to their peripubertal status and not to the inhalation of o-phthalaldehyde.

Inhalation of o-phthalaldehyde resulted in significantly decreased testis, epididymis, and cauda epididymis weights in rats exposed to 0.88 ppm and 1.75 ppm. Additionally, there were degenerative changes in the testes of rats exposed to 3.5 ppm that survived beyond 39 days. These changes included seminiferous tubule vacuolation with focal loss of germ cells from individual Sertoli cells and degeneration and depletion of elongated spermatids. Vacuolation is a common morphological response of the Sertoli cell to toxicant-induced injury.^75^ As vacuolation is an early event, it is typically followed by degeneration, disorganization, or exfoliation of the germ cells, depending on the nature of the Sertoli cell functional disturbance.^76^ This typically results in the appearance of these exfoliated germ cells within the epididymis.^77^ In the current studies, some incidences of exfoliated germ cells were observed in the epididymis of rats and mice. Damage to epididymal sperm can have an immediate impact on fertility parameters. Percent sperm motility was significantly reduced in an exposure concentration-related manner in both rats and mice in all exposed groups evaluated, compared to the chamber control groups. Additionally, rats had significantly lower absolute weights of the left cauda epididymis, left epididymis, and left testis in the 0.88 and 1.75 ppm groups; exposed mice did not have decreased absolute testis or epididymis weights. There were no chemical-related microscopic changes in the testis or epididymis of rats or mice exposed to 0.44, 0.88, or 1.75 ppm that would explain the significant exposure concentration-dependent decreases in sperm motility in rats and mice. Either the changes were below the level of histologic detection, or there were physiological changes that resulted in decreased motility. Taken together, the changes in sperm parameters, testis and epididymis weights, and microscopic findings suggest that o-phthalaldehyde has the potential to be a male reproductive toxicant in rats and mice.

Under the conditions of these 3-month inhalation studies, there were treatment-related lesions in male and female rats and mice. The major targets from o-phthalaldehyde exposure in rats and mice included the respiratory system (nasal cavity, larynx, trachea, and lung), skin, eye, testis, and epididymis. The most sensitive measure of o-phthalaldehyde inhalation toxicity in male and female rats and mice was significantly increased incidences of nasal cavity lesions (lowest-observable-effect concentration = 0.44 ppm). A no-observed-effect concentration was not determined in rats or mice of either sex.