# Materials and Methods

## Procurement and Characterization of o-Phthalaldehyde

o-Phthalaldehyde was obtained from MP Biomedicals, LLC (Solon, OH), in one lot (8674J) that was used during the 3-month studies. Identity and purity analyses were conducted by the study laboratory at Battelle Toxicology Northwest (Richland, WA) and by the analytical chemistry laboratory at Chemir Analytical Services (Maryland Heights, MO) (Appendix F). Reports on analyses performed in support of the o-phthalaldehyde studies are on file at the National Institute of Environmental Health Sciences.

Lot 8674J of the chemical, a pale-yellow, coarse, crystalline material, was identified as o-phthalaldehyde by the study laboratory using infrared spectroscopy, and by the analytical chemistry laboratory using Fourier transform infrared and proton nuclear magnetic resonance (NMR) spectroscopy. All spectra were consistent with literature spectra and the structure of o-phthalaldehyde.

The analytical chemistry laboratory determined the moisture content of lot 8674J using Karl Fischer titration and elemental analyses for carbon, hydrogen, nitrogen, and sulfur using inductively coupled plasma/optical emission spectroscopy. The study laboratory determined the purity of lot 8674J directly as well as relative to a commercial o-phthalaldehyde standard using gas chromatography (GC) with flame ionization detection (FID), and GC with mass spectrometry (MS) for identification of impurities.

For lot 8674J, Karl Fischer titration indicated approximately 0.12% water; elemental analyses for carbon and hydrogen were in agreement with the theoretical values for o-phthalaldehyde. GC/FID indicated one major peak that was 99% of the total peak area and three impurities that were each over 0.1% of the total peak area, with a combined total of approximately 1% of the total peak area. Two of the impurities were tentatively identified as toluene and phthalide by comparison of GC retention times to a chromatogram obtained from a standard solution containing possible impurities or degradation products that included toluene, phthalide, benzaldehyde, phthalan, N-hydroxyphthalimide, naphthalene, isophthalaldehyde, and terepthaldicarboxaldehyde. The third peak was not identified. GC/MS indicated that the phthalide peak also contained phthalic acid, which eluted at the same retention time. Different GC columns of varying polarity with FID were used but failed to resolve these two compounds. To ensure the absence of certain degradation products, GC/FID was used to determine the presence of acetonitrile, GC/MS was used for chloroform, and high-performance liquid chromatography with ultraviolet UV detection (HPLC/UV) was used for 2-carboxybenzaldehyde. Acetonitrile and chloroform were less than 0.1% and 2-carboxybenzaldehyde was approximately 0.4% by weight. The overall purity of lot 8674J was determined to be greater than 99%. The purity relative to the commercial standard was greater than 99.7%. To ensure stability, the test chemical was stored refrigerated in the original sealed plastic containers. Periodic reanalyses of the bulk chemical were performed during the 3-month studies using GC/FID, GC/MS, and HPLC/UV, and no degradation of the test chemical occurred.

## Vapor Generation and Exposure System

o-Phthalaldehyde vapor was generated from a flask heated with a heating mantle, purged by a heated nitrogen flow entering above the flask area, blended with heated dilution air to obtain the vapor concentration desired, and transported into a distribution manifold located above the generator. Vapor concentration was determined by the reservoir temperature, nitrogen flow rate, and dilution air flow rate. Pressure in the distribution manifold was fixed to ensure constant flows through the manifold and into the chambers.

Due to the high boiling point of o-phthalaldehyde, all vapor transport lines and the on-line GC transport sample line of the 7.0 ppm chambers were heated above the minimum temperature needed to transport vapor without condensation. Individual Teflon^®^-delivery lines carried the vapor from the distribution manifold to three-way exposure valves at the chamber inlets. The exposure valves diverted vapor from the metering valves to exposure chamber exhaust until the generation system stabilized and exposure could proceed; an additional 60 minutes was added to the prestart stabilization time to purge residual toluene present in the test chemical to less than 1% before exposures began. To initiate exposure, the chamber exposure valves were rotated to allow the vapor to flow to each chamber exposure duct where it was diluted with conditioned chamber air to achieve the desired exposure concentration.

The study laboratory designed the inhalation exposure chamber (Harford Systems Division of Lab Products, Inc., Aberdeen, MD) so that uniform vapor concentrations could be maintained throughout the chamber with the catch pans in place. The total active mixing volume of each chamber was 1.7 m^3^. A small particle detector (Model 3022A; TSI Inc., St. Paul, MN) was used with and without animals in the exposure chambers to ensure that o-phthalaldehyde vapor, and not aerosol, was produced. No particle counts above the minimum resolvable level (approximately 200 particles/cm^3^) were detected.

## Vapor Concentration Monitoring

Summaries of the chamber vapor concentrations are given in Table F-2. Concentrations of o-phthalaldehyde in exposure chambers were monitored by an on-line GC/FID system. Samples were drawn from all exposure and control chambers approximately every 20 minutes during each exposure period using Hasteloy-C stream-select and gas-sampling valves (VALCO Instruments Company, Houston, TX) in a separate, heated oven. The sampling lines composing the sample loop were made from Teflon^®^ tubing and were connected to the exposure chamber relative humidity sampling lines near the gas chromatograph. A vacuum regulator maintained a constant vacuum in the sample loop to compensate for variations in sample line pressure. An in-line flow meter between the vacuum regulator and the gas chromatograph allowed digital measurement of sample flow. The on-line gas chromatograph was checked throughout the day for instrument drift against an on-line standard vapor of o-phthalaldehyde in nitrogen supplied by a standard generator (Kin-Tek; Precision Calibration Systems, La Marque, TX). The on-line gas chromatograph was checked before the start of each exposure day and after every tenth sample throughout the exposure period. The on-line gas chromatograph was calibrated prior to the start of the study and at least monthly by a comparison of chamber concentration data to data from grab samples that were collected with adsorbent gas sampling tubes containing silica gel (ORBO-52^TM^; Supelco, Bellefonte, PA), extracted with acetonitrile containing α-terpineol as an internal standard, and analyzed using an off-line GC/FID system. Originally, the grab samples were located within the whole body exposure chambers; however, after animals were transferred into the chambers, ammonia produced by the action of fecal bacteria on urine^37^ caused inaccurate measurements of exposure concentration; sampling tubes were moved within the inlet lines. Additional samples were collected from the on-line standard generator to bracket concentrations found in the exposure chambers. The off-line gas chromatograph was calibrated with gravimetrically prepared standards of o-phthalaldehyde and the internal standard (α-terpineol) in acrylonitrile.

## Chamber Atmosphere Characterization

Buildup and decay rates for chamber vapor concentrations were determined with and without animals present in the chambers. At a chamber airflow rate of 15 air changes per hour, the theoretical value for the time to achieve 90% of the target concentration after the beginning of vapor generation (T_90_) and the time for the chamber concentration to decay to 10% of the target concentration after vapor generation was terminated (T_10_) was approximately 9.2 minutes. For rats and mice in the 3-month studies, T_90_ values ranged from 15 to 21 minutes without animals present and from 24 to 35 minutes with animals; T_10_ values ranged from 10 to 18 minutes without animals present and from 14 to 39 minutes with animals. A T_90_ value of 17 minutes was used for these studies.

The uniformity of vapor concentration in the inhalation exposure chambers without animals was evaluated before each of the studies began; in addition, concentration uniformity with animals present in the chambers was measured once during the 3-month studies. The vapor concentration was measured using the on-line GC/FID system. The automatic 12-port sample valve was disabled to allow continuous monitoring from a single input line. Samples were collected from 12 positions in each chamber. Chamber concentration uniformity was maintained throughout the studies.

The persistence of o-phthalaldehyde in the chambers after vapor delivery ended was determined by monitoring the vapor concentration overnight in the 7.0 ppm chamber without and with animals present in the chambers. The concentration decreased to 1% of the target concentration within 128 minutes without animals present and 279 minutes with animals present. Stability studies of the test chemical were performed by the study laboratory on the distribution line and 7.0 and 0.44 ppm exposure chambers without animals present and on the 3.5 and 0.44 ppm exposure chambers with animals present. Samples were collected with two adsorbent tubes in series during the first and last hours of generation, extracted with acetonitrile (internal standard, α-terpineol) and analyzed using GC/FID. Samples were also collected from the generator reservoir. The presence of chloroform, acetonitrile, and 2-carboxybenzaldehyde in the exposure atmosphere was investigated using samples collected on ORBO-52^TM^ tubes by GC/FID (acetonitrile and chloroform) or HPLC/UV (2-carboxybenzaldehyde). These studies indicated that the o-phthalaldehyde test material was stable for 1 day.

## Animal Source

Male and female Sprague Dawley (Hsd:Sprague Dawley^®^ SD^®^) rats were obtained from Harlan Laboratories, Inc., (Livermore, CA), and B6C3F1/N mice were obtained from the NTP colony maintained at Taconic Biosciences, Inc. (formerly Taconic Farms, Germantown, NY).

## Animal Welfare

Animal care and use are in accordance with the Public Health Service Policy on Humane Care and Use of Animals. All animal studies were conducted in an animal facility accredited by the Association for the Assessment and Accreditation of Laboratory Animal Care International. Studies were approved by the Battelle Toxicology Northwest Animal Care and Use Committee and conducted in accordance with all relevant NIH and NTP animal care and use policies and applicable federal, state, and local regulations and guidelines.

## Three-month Studies

On receipt, the rats and mice were 4 to 5 weeks old. Animals were quarantined for 12 to 13 days and were 6 weeks old on the first day of the studies. Before the studies began, five male and five female rats and mice were randomly selected for parasite evaluation and gross observation for evidence of disease. The health of the animals was monitored during the studies according to the protocols of the NTP Sentinel Animal Program (Appendix H). All results were negative.

Groups of 10 male and 10 female rats and mice were exposed to o-phthalaldehyde via whole-body inhalation at concentrations of 0, 0.44, 0.88, 1.75, 3.5, or 7.0 ppm, 6 hours plus T_90_ (17 minutes) per day, 5 days per week for 14 weeks. In addition, groups of 10 male and 10 female clinical pathology rats were exposed to the same concentrations for 23 days. Feed was available ad libitum except during exposure periods; water was available ad libitum. Rats and mice were housed individually. Clinical findings were recorded on day 8, weekly thereafter, and at the end of the studies for core animals. Feed consumption was recorded weekly by cage. The animals were weighed initially, weekly, and at the end of the studies. Details of the study design and animal maintenance are summarized in Table 1. Information on feed composition and contaminants are provided in Appendix G.

Table 1 Experimental Design and Materials and Methods in the Three-month Inhalation Studies of o-Phthalaldehyde

Three-month Studies
Study Laboratory
Battelle Toxicology Northwest (Richland, WA)
Strain and Species
Sprague Dawley (Hsd:Sprague Dawley^®^ SD^®^) rats
B6C3F1/N mice
Animal Source
Rats: Harlan Laboratories, Inc. (Livermore, CA)
Mice: Taconic Biosciences, Inc. (Germantown, NY)
Time Held Before Studies
Rats: 12 (males) or 13 (females) days Mice: 12 days
Average Age When Studies Began
Rats: 6 weeks Mice: 5 to 6 weeks
Date of First Exposure
Rats: January 19 (males) or 20 (females), 2009 Mice: January 19, 2009
Duration of Exposure
6 hours plus T_90_ (17 minutes), 5 days/week for 14 weeks
Date of Last Exposure
Rats: April 20 (males) or 21 (females), 2009 Mice: April 22 (males) or 23 (females), 2009
Necropsy Dates
Rats: April 21 (males) or 22 (females), 2009 Mice: April 23 (males) or 24 (females), 2009
Average Age at Necropsy
19 to 20 weeks
Size of Study Groups
10 males and 10 females
Method of Distribution
Animals were distributed randomly into groups of approximately equal initial mean body weights.
Animals per Cage
1
Method of Animal Identification
Tail tattoo
Diet
NTP-2000 irradiated wafer diet (Zeigler Brothers, Inc., Gardners, PA), available ad libitum except during exposure periods, changed weekly
Water
Tap water (Richland municipal water supply) via automatic watering system (Edstrom Industries, Inc., Waterford, WI), available ad libitum
Cages
Stainless steel wire-bottom (Lab Products, Inc., Seaford, DE), changed and rotated weekly
Cageboard
Untreated paper (Shepherd Specialty Papers, Watertown, TN), changed daily
Chamber Air Supply Filters
Single HEPA, charcoal (RSE, Inc., New Baltimore, MI), Purafil (Environmental Systems, Lynnwood, WA); all new at study start
Chambers
Stainless steel, excreta pan at each of six levels (Lab Products, Inc., Seaford, DE), chambers changed weekly; excreta pans changed daily
Chamber Environment
Temperature: 75° ± 3°F Relative humidity: 55% ± 15% Room fluorescent light: 12 hours/day Room air changes: 15 ± 2/hour
Exposure Concentrations
0, 0.44, 0.88, 1.75, 3.5, and 7.0 ppm
Type and Frequency of Observation
Observed twice daily; core study animals were weighed initially, on day 8, weekly, and at the end of the studies; clinical findings were recorded on day 8, weekly, and at the end of the studies.
Method of Euthanasia
Carbon dioxide asphyxiation
Necropsy
Necropsies were performed on core study animals. Organs weighed in the chamber control, 0.44, 0.88, 1.75, and 3.5 ppm groups were heart, right kidney, liver, lung, right testis, and thymus.
Clinical Pathology
Blood was collected via the retroorbital plexus from surviving clinical pathology rats on days 3 and 23 and from all core study rats surviving to the end of the study for hematology and clinical chemistry. Blood was collected from the retroorbital sinus of mice at the end of the study for hematology. Hematology: hematocrit; hemoglobin concentration; erythrocyte, reticulocyte, and platelet counts; erythrocyte, leukocyte, and platelet morphology; mean cell volume; mean cell hemoglobin; mean cell hemoglobin concentration; leukocyte count and differentials, and packed cell volume. Clinical chemistry: urea nitrogen, creatinine, glucose, total protein, albumin, cholesterol, globulin, albumin/globulin ratio, triglycerides, alanine aminotransferase, alkaline phosphatase, creatine kinase, sorbitol dehydrogenase, and bile acids
Histopathology
Histopathology was performed on core study chamber control rats and mice, male rats and mice exposed to 1.75, 3.5, or 7.0 ppm, and female rats and mice exposed to 3.5 or 7.0 ppm. In addition to gross lesions and tissue masses, the following tissues were examined: adrenal gland, bone with marrow, brain, clitoral gland, esophagus, eye, Harderian gland, gallbladder (mice), heart, large intestine (cecum, colon, rectum), small intestine (duodenum, jejunum, ileum), kidney, larynx, liver, lung, lymph nodes (mandibular, mesenteric, bronchial, and mediastinal), mammary gland, nose, ovary, pancreas, parathyroid gland, pharynx, pituitary gland, preputial gland, prostate gland, salivary gland, seminal vesicle, skin, spleen, stomach (forestomach and glandular), thymus, thyroid gland, trachea, urinary bladder, and uterus. Tissues were examined to a no-effect level in the remaining core study groups. In addition, the pinna was examined in chamber control and 7.0 ppm mice and the testis with epididymis was examined in all male rats and mice. The testis with epididymis from two untreated 45-day-old rats were also examined.
Sperm Motility
At the end of the studies, spermatid and sperm samples were collected from male rats and mice in the 0, 0.44, 0.88, and 1.75 ppm groups. The following parameters were evaluated: spermatid heads per testis and per gram testis, sperm motility, and sperm per cauda epididymis and per gram cauda epididymis. The left cauda, left epididymis, and left testis were weighed.

Animals were anesthetized with carbon dioxide, and blood was collected from the retroorbital plexus of 10 male and 10 female clinical pathology rats on days 3 and 23 and from core study rats at the end of the study for hematology and clinical chemistry analyses. Blood was collected from the retroorbital sinus of mice at the end of the study for hematology analyses. Blood samples for hematology analyses were collected into tubes containing potassium EDTA. Packed cell volume; hemoglobin concentration; erythrocyte, platelet, leukocyte, and leukocyte differential counts; mean cell volume; mean cell hemoglobin; and mean cell hemoglobin concentration were determined using an Abbott Cell-Dyn 3700 Analyzer (Abbott Diagnostics Systems, Abbott Park, IL). Manual hematocrit values were determined using a microcentrifuge (Heraeus Haemofuge; Heraeus Holding GmbH; Hanau, Germany) and a Damon/IEC capillary reader (International Equipment Co., Needham Heights, MA) for comparison to Cell-Dyn values for packed cell volume. Blood smears were stained with Romanowsky-type aqueous stain in a Wescor 7120 aerospray slide stainer (Wescor, Inc., Logan, UT), and blood cell morphologies were examined; the number of nucleated erythrocytes was also noted and the leukocyte count adjusted accordingly. Manual leukocyte differential counts were performed in the event of flagged automated counts. The manual leukocyte differential was based on classifying a minimum of 100 white cells. Reticulocytes were stained with New Methylene Blue and enumerated as a reticulocyte:erythrocyte ratio using the Miller disc method.^38^ Blood samples for clinical chemistry analyses were placed in tubes without anticoagulant and containing a separator gel, allowed to clot, and centrifuged. Parameters were determined using a Roche Hitachi 912 System (Roche Diagnostic Corporation, Indianapolis, IN). Parameters measured are listed in Table 1.

At the end of the 3-month studies, samples were collected for sperm motility and vaginal cytology evaluations on rats and mice exposed to 0, 0.44, 0.88, or 1.75 ppm. The parameters evaluated are listed in Table 1. For 16 consecutive days prior to scheduled terminal euthanasia, the vaginal vaults of the females were moistened with saline, and samples of vaginal fluid and cells were collected and subsequently stained; however, due to inconsistent sample collection and slide staining, an assessment of estrous cyclicity could not be made. Male animals were evaluated for sperm count and motility. The left testis and left epididymis were isolated and weighed. The tail of the epididymis (cauda epididymis) was then removed from the epididymal body (corpus epididymis) and weighed. Test yolk (rats) or modified Tyrode’s buffer (mice) was applied to slides and a small incision was made at the distal border of the cauda epididymis. The sperm effluxing from the incision were dispersed in the buffer on the slides, and the numbers of motile and nonmotile spermatozoa were counted for five fields per slide by two observers. Following completion of sperm motility estimates, each left cauda epididymis was placed in buffered saline solution. Caudae were finely minced, and the tissue was incubated in the saline solution and then heat fixed at 65°C. Sperm density was then determined microscopically with the aid of a hemacytometer. To quantify spermatogenesis, the testicular spermatid head count was determined by removing the tunica albuginea and homogenizing the left testis in phosphate-buffered saline containing 10% dimethyl sulfoxide. Homogenization-resistant spermatid nuclei were counted with a Hamilton Thorne Bioscience Integrated Visual Optical System following homogenization in buffer using a Brinkman Polytron with generator.

Necropsies were performed on core study rats and mice. The heart, right kidney, liver, lungs, right testis, and thymus were weighed. Tissues for microscopic examination were fixed and preserved in 10% neutral buffered formalin (except eyes were fixed in Davidson’s solution and testes, vaginal tunics, and epididymides were first fixed in modified Davidson’s solution) processed and trimmed, embedded in paraffin, sectioned to a thickness of 4 to 6 µm, and stained with hematoxylin and eosin. Complete histopathologic examinations were performed by the study laboratory pathologist on core study chamber control rats and mice, male rats and mice exposed to 1.75, 3.5, or 7.0 ppm and female rats and mice exposed to 3.5 or 7.0 ppm. Table 1 lists the tissues and organs routinely examined.

In addition to the routinely examined tissues and organs, there were special histopathologic reviews of the skin, testes, and epididymides in these studies. Although clinical findings of black skin pigmentation were noted on distal appendages (pinnae and/or feet) during in-life exposure in rats, pinnae were not available for histopathology in rats but were available for mice. Therefore, histopathologic evaluation included the left pinna in chamber control and 7.0 ppm mice (both sexes) based on clinical findings of black discoloration on distal appendages in rats, lesions noted in routine inguinal skin sections in mice, and scientific literature reporting contact dermatitis/chemical burns associated with o-phthalaldehyde exposure in humans.^25,29^ As part of the special review of testes and epididymides, tissues from two untreated 45-day-old rats were examined to ascertain histopathologic features typical of peripuberty to compare to testes and epididymides from rats that died in the first 2 weeks of the study, prior to sexual maturity.

After a review of the laboratory reports and selected histopathology slides by a quality assessment (QA) pathologist, the findings and reviewed slides were submitted to a NTP Pathology Working Group (PWG) coordinator for a second independent review. Any inconsistencies in the diagnoses made by the study laboratory and QA pathologists were resolved by the NTP pathology peer review process. Final diagnoses for reviewed lesions represent a consensus of the PWG or a consensus between the study laboratory pathologist, NTP pathologist, QA pathologist(s), and the PWG coordinators. Special pathology peer reviews were convened following the initial PWG to evaluate the testes and epididymides. Details of these review procedures have been described, in part, by Maronpot and Boorman^39^ and Boorman et al.^40^

## Statistical Methods

### Calculation and Analysis of Lesion Incidences

The incidences of lesions are presented in Appendix A as numbers of animals bearing such lesions at a specific anatomic site and the numbers of animals with that site examined microscopically. The Fisher exact test,^41^ a procedure based on the overall proportion of affected animals, was used to determine significance between exposed and chamber control animals, and the Cochran-Armitage trend test was used to test for significant trends.^42^

### Analysis of Continuous Variables

Two approaches were employed to assess the significance of pairwise comparisons between dosed and control groups in the analysis of continuous variables. Organ and body weight data, which historically have approximately normal distributions, were analyzed with the parametric multiple comparison procedures of Dunnett^43^ and Williams.^44,45^ Hematology, clinical chemistry, spermatid, and epididymal spermatozoal data, which have typically skewed distributions, were analyzed using the nonparametric multiple comparison methods of Shirley^46^ (as modified by Williams^47^) and Dunn.^48^ Jonckheere’s test^49^ was used to assess the significance of the dose-related trends and to determine whether a trend-sensitive test (Williams’ or Shirley’s test) was more appropriate for pairwise comparisons than a test that does not assume a monotonic dose-related trend (Dunnett’s or Dunn’s test). Prior to statistical analysis, extreme values identified by the outlier test of Dixon and Massey^50^ were examined by NTP personnel, and implausible values were eliminated from the analysis.

## Quality Assurance Methods

The 3-month studies were conducted in compliance with Food and Drug Administration Good Laboratory Practice Regulations.^51^ In addition, as records from the 3-month studies were submitted to the NTP Archives, these studies were audited retrospectively by an independent QA contractor. Separate audits covered completeness and accuracy of the pathology data, pathology specimens, final pathology tables, and a draft of this NTP Toxicity Study Report. Audit procedures and findings are presented in the reports and are on file at NIEHS. The audit findings were reviewed and assessed by NTP staff, and all comments were resolved or otherwise addressed during the preparation of this Toxicity Study Report.

## Genetic Toxicology

### Bacterial Mutagenicity Test Protocol

o-Phthalaldehyde was tested for bacterial mutagenicity using test protocols that were modified from Zeiger et al.^52^ Briefly, o-phthalaldehyde was incubated with Salmonella typhimurium tester strains TA98 and TA100 and an Escherichia coli strain WP2 uvrA/pKM101, either in buffer or S9 mix (metabolic activation enzymes and cofactors from Aroclor 1254-induced male Sprague Dawley rat liver) for 20 minutes at 37º C. Top agar supplemented with l-histidine (for the S. typhimurium strains) or tryptophan (for the E. coli strain) and d-biotin was added, and the contents of the tubes were mixed and poured onto the surfaces of minimal glucose agar plates. Histidine- or tryptophan-independent mutant colonies arising on these plates were counted following 2 days incubation at 37ºC.

Each trial consisted of triplicate plates of concurrent positive and negative controls and of five doses of test article; the highest concentration tested was limited by toxicity.

In this assay, a positive response is defined as a reproducible, dose-related increase in histidine-independent (revertant) colonies in any one strain/activation combination. An equivocal response is defined as an increase in revertants that is not dose-related, is not reproducible, or is not of sufficient magnitude to support a determination of mutagenicity. A negative response is obtained when no increase in revertant colonies is observed following chemical treatment. There is no minimum percentage or fold-increase required for a chemical to be judged positive or weakly positive, although positive calls are typically reserved for increases in mutant colonies that are at least twofold over background.

### Rat and Mouse Peripheral Blood Micronucleus Test Protocol

At the end of the 3-month studies, blood samples were collected from surviving rats and mice, placed into EDTA tubes, chilled, and shipped overnight to the testing laboratory At the testing laboratory, samples were fixed in ultracold methanol, and frozen at −80°C until analysis. Thawed blood samples were analyzed for frequency of micronucleated reticulocytes (PCEs) and erythrocytes (NCEs) using a flow cytometer^53^; both the mature erythrocyte population and the immature reticulocyte population can be accurately distinguished by employing special cell surface markers to differentiate the two cell types. Approximately 20,000 reticulocytes and 1 million erythrocytes were analyzed per animal; the percentage of reticulocytes among circulating erythrocytes was also determined as a measurement of bone marrow toxicity.

Based on prior experience with the large number of cells scored using flow cytometric scoring techniques,^54^ it is reasonable to assume that the proportion of micronucleated reticulocytes is approximately normally distributed. The statistical tests selected for trend and for pairwise comparisons with the chamber control group depend on whether the variances among the groups are equal. Levene’s test at α = 0.05 is used to test for equal variances. In the case of equal variances, linear regression is used to test for a linear trend with dose and Williams’ test is used to test for pairwise differences between each treatment group and the control group. In the case of unequal variances, Jonckheere’s test is used to test for linear trend and Dunn’s test is used for pairwise comparisons of each treatment group with the control group. To correct for multiple pairwise comparisons, the P value for each comparison with the control group is multiplied by the number of comparisons made. In the event that this product is greater than 1.00, it is replaced with 1.00. Trend tests and pairwise comparisons with the controls are considered statistically significant at P ≤ 0.025. Ultimately, the scientific staff determines the final call after considering the results of statistical analyses, reproducibility of any effects observed, and the magnitudes of those effects.

### Evaluation Protocol

These are the basic guidelines for arriving at an overall assay result for assays performed by the National Toxicology Program. Statistical as well as biological factors are considered. For an individual assay, the statistical procedures for data analysis have been described in the preceding protocols. There have been instances, however, in which multiple samples of a chemical were tested in the same assay, and different results were obtained among these samples and/or among laboratories. Results from more than one aliquot or from more than one laboratory are not simply combined into an overall result. Rather, all the data are critically evaluated, particularly with regard to pertinent protocol variations, in determining the weight of evidence for an overall conclusion of chemical activity in an assay. In addition to multiple aliquots, the in vitro assays have another variable that must be considered in arriving at an overall test result. In vitro assays are conducted with and without exogenous metabolic activation. Results obtained in the absence of activation are not combined with results obtained in the presence of activation; each testing condition is evaluated separately. The results presented in the Abstract of this Toxicity Study Report represent a scientific judgment of the overall evidence for activity of the chemical in an assay.