# Introduction

Figure 1

o-Phthalaldehyde (CASRN 643-79-8; Chemical Formula: C_8_H_6_O_2_; Molecular Weight: 134.13)

Synonyms: 1,2-Benzenedicarboxaldehyde; o-phthaldialdehyde; phthalic aldehyde.

## Chemical and Physical Properties

o-Phthalaldehyde is a pale yellow crystalline solid with a specific gravity of 0.63 ± 0.10 g/mL at 20°C, a melting point of 55° to 58°C, a boiling point of 266° ± 23°C at 760 mm Hg, and a vapor pressure of 0.0052 mm Hg at 21°C.^1,2^ The solubility of o-phthalaldehyde is 3 g/100 mL diisopropyl ether, 5 g/100 mL deionized water, 20 g/100 mL chloroform, or 20 g/100 mL acetone at 20°C.

## Production, Use, and Human Exposure

A variety of processes for manufacturing o-phthalaldehyde have been reported in the literature. o-Phthalaldehyde is produced by heating pure benzaldehyde and chloroform with potassium hydroxide solution.^3^ The resulting solution is further acidified with hydrochloric acid and cooled to yield a colorless powder of o-phthalaldehyde. o-Phthalaldehyde is also produced by ozonization of naphthalene in alcohol followed by catalytic hydrogenation.^4^ Catalytic oxidation of various chemicals is also used in manufacturing o-phthalaldehyde. o-Phthalaldehyde can be manufactured by oxidation of phthalan by nitrogen monoxide in acetonitrile with N-hydroxyphthalimide as the catalyst to yield 80% to 90% o-phthalaldehyde.^5^ Also, 76% to 99.9% o-phthalaldehyde can be produced by oxidation of α-dichloro-o-xylene with aqueous nitric acid solution in the presence of vanadium pentoxide as the catalyst.^6^ Oxidation of o-xylylene oxide and/or o-xylylene glycol with nitric acid solution followed by a purification step yields 35% to 72% o-phthalaldehyde.^7^ In addition, oxidation of o-phthalaldehyde tetraalkyl acetals by an electrochemical technique is also used to produce o-phthalaldehyde.^8,9^

o-Phthalaldehyde is mainly used as a high-level disinfectant (a low-temperature chemical method) for heat-sensitive medical and dental equipment such as endoscopes and thermometers^10^; in recent years, it has gained popularity as a safe and better alternative to glutaraldehyde. Glutaraldehyde is a widely used chemical disinfectant for heat-sensitive equipment, but it has been associated with health effects such as dermatitis and occupational asthma.^11^ Along with its increasing popularity as a chemical sterilizer, o-phthalaldehyde has many applications in analytical methods and in diagnostic kits. o-Phthalaldehyde is also used as an intermediate in the synthesis of pharmaceuticals and as a reagent in the tanning industry, hair colorings, wood treatment, and antifouling paints. o-Phthalaldehyde was approved for use as an indoor antimicrobial pesticide in 1997; however, it is no longer registered with the United States Environmental Protection Agency (USEPA) for this use.^12^

The primary routes of human exposure to o-phthalaldehyde are by inhalation and through the skin, which may occur through accidental or occupational exposures. Many case reports document accidental exposure of patients to o-phthalaldehyde through use of medical equipment (e.g., transesophageal electroradiography probes and colonoscopes) that have been sterilized with the compound and inadequately rinsed. Occupational exposure to o-phthalaldehyde vapor or liquid occurs primarily in the health care industry, during chemical sterilization of medical equipment in hospital settings. o-Phthalaldehyde has been detected in air samples from several endoscopy units (1.0 to 13.5 ppb) in hospitals in Italy and the United States.^13,14^ Data from the 1981 to 1983 National Occupational Exposure Survey conducted by the National Institute for Occupational Safety and Health^15^ indicates that 3,253 workers such as geologists, geodesists, clinical laboratory technologists and technicians, engineering technicians, and chemical technicians were potentially exposed to o-phthalaldehyde in the workplace. During the same period, more than 318,362 workers were potentially exposed to glutaraldehyde in the healthcare field alone. Based on the rising popularity of o-phthalaldehyde as a replacement for glutaraldehyde, it is reasonable to assume that more than 300,000 healthcare workers are currently being exposed to o-phthalaldehyde. In 2009 and 2010, the Health Hazard Evaluation Program through the Centers for Disease Control and Prevention (CDC) and NIOSH, which evaluated eight health care facilities across the country for o-phthalaldehyde-specific health practices, assessed the exposures and potential health risks of employees to o-phthalaldehyde.^16^ Across the eight facilities, the full shift, time-weighted average o-phthalaldehyde concentrations ranged from not detected (ND) to 38 μg/m^3^ (0.007 ppm), which is higher than the range that was measured in the control group [ND to 0.67 μg/m^3^ (0.0001 ppm)].

## Regulatory Status

o-Phthalaldehyde is commercially available as Cidex^®^ OPA concentrate (5.75% o-phthalaldehyde) or Cidex^®^ OPA ready to use 0.55% aqueous solution (0.55% o-phthalaldehyde and 99.45% water) (Advanced Sterilization Products, Irvine, CA). Other solutions containing o-phthalaldehyde as a sterilization ingredient include Opaciden Solution (0.6%) (Ciden Technologies, LLC) and Rapicide OPA-28 (0.575%) (Minntech Corporation).^17^ o-Phthalaldehyde is also listed as 1,2-benzenedicarboxaldehyde in the active ingredients of UCARCIDE^TM^ P200 Antimicrobial (99.8%) (Dow Chemical Company, Midland, MI) and Cidex^®^ OPA Antimicrobial (99.7%) (Johnson & Johnson Medical, Inc.). The product registrations as pesticides with the USEPA for both the UCARCIDE^TM^ P200 and Cidex^®^ OPA Antimicrobial were cancelled in 2005 and 1998, respectively.

Currently, the above commercial products containing o-phthalaldehyde (0.55% to 5.75%) have received United States Food and Drug Administration market approval as high-level chemical disinfectants for chemical sterilization of medical devices. With regard to occupational exposures to o-phthalaldehyde, there are no existing Occupational Safety and Health Administration (OSHA) or NIOSH recommendations or promulgated standards for exposure limits to the chemical in occupational settings. Similarly, no recommended guidelines have been published by the American Conference of Governmental Industrial Hygienists (ACGIH) for o-phthalaldehyde. Though there is no personal exposure limit established by OSHA for o-phthalaldehyde, glutaraldehyde has a NIOSH Recommended Exposure Limit of 0.2 ppm (0.8 mg/m^3^) and the ACGIH recommends a Threshold Limit Value of 0.05 ppm in air.^18^

## Absorption, Distribution, Metabolism, and Excretion

### Experimental Animals

Limited information on the disposition and metabolism of o-phthalaldehyde in experimental animals was found in the literature. In male rats (strain not specified) following intratracheal or oral administration of [^14^C]-o-phthalaldehyde, the absorption was rapid with peak plasma concentrations occurring at 0.8 and 1.7 hours, respectively.^19^ The radioactivity was cleared at a similar rate following the two routes of exposure with a terminal phase half-life of approximately 94 hours. The excretion in urine and feces was 44% and 11%, respectively, 72 hours after intratracheal administration. Urinary excretion following oral administration was similar to intratracheal administration with 43% of the radiolabel excreted 72 hours after dosing; feces contained 50% of the radiolabel, suggesting incomplete absorption following oral administration. In addition, residual radioactivity in carcasses following intratracheal and oral administration was 41% and 2%, respectively. The major urinary products identified were 2-carboxybenzaldehyde (phthalaldehydic acid) (33%) and phthalic anhydride (4%); parent o-phthalaldehyde was not detected.

### Humans

No data describing the in vivo fate of o-phthalaldehyde in humans were found in a review of the literature.

## Toxicity

### Experimental Animals

The oral LD_50_ of a commercially used solution containing 0.55% o-phthalaldehyde (Cidex^®^ OPA) was reported to be greater than 5,000 mg/kg in rats.^20^ The LD_50_ in mice after intraperitoneal injection of a 99.8% o-phthalaldehyde solution was 27 mg/kg^21^ and the dermal LD_50_ of Cidex^®^ OPA was reported to be greater than 2,000 mg/kg in rabbits.^20^ Animal toxicity data are limited and no acute, subchronic, or chronic toxicity studies of o-phthalaldehyde are reported in the scientific literature. In rats, the no-observed-effect level of o-phthalaldehyde has been reported to be 5 mg/kg per day following oral administration; however, experimental details of the reporting study have not been published in the literature.^20^

The immunotoxicity of o-phthalaldehyde has been investigated in numerous studies in mice. ICR mice were injected subcutaneously with 0.0025%, 0.0125%, 0.025%, 0.125% or 0.25% o-phthalaldehyde with or without ovalbumin (OVA) on days 0 and 5 and challenged with 10 µg of OVA on days 18 or 19.^22^ Increased neutrophil infiltration in the bronchoalveolar fluid and production of OVA-specific IgE in o-phthalaldehyde-treated mice indicated that it is an effective immunological adjuvant. Furthermore, based on increases in IL-4 and IL-5 gene expression, the authors concluded that o-phthalaldehyde induces Th2-type immune responses. In another study, ICR mice were injected subcutaneously twice on days 0 and 5 with 0.125%, 0.25%, 0.3125%, 0.375%, or 0.5% o-phthalaldehyde and observed for 18 days.^23^ The animals developed systemic inflammation and liver injury due to acute toxicity. o-Phthalaldehyde acted as a hapten and induced immunological responses. A significant dose–dependent increase in o-phthalaldehyde-specific IgG and IgE was observed in the serum of mice treated with repeat doses of o-phthalaldehyde.

Dermal sensitization studies conducted in female Balb/c mice identified o-phthalaldehyde as an irritant and contact sensitizer.^24^ The sensitizing potency of o-phthalaldehyde measured by the ear swelling test and local lymph node assay (LLNA) was demonstrated to be similar to the sensitizing potency of glutaraldehyde. In the LLNA, statistically significant increases in lymph node cell proliferation were observed with the top two test concentrations (0.1% and 0.75%). An EC3 value (the estimated concentration required to induce a threefold or greater increase in proliferative activity compared with concurrent vehicle treated controls) of 0.051% was calculated, suggesting that o-phthalaldehyde is a strong sensitizer. Mechanistically, o-phthalaldehyde exposure resulted in increased numbers of IgE-positive B cells in the draining lymph nodes of o-phthalaldehyde-treated mice. Increased serum levels of total IgE, o-phthalaldehyde-specific IgE and o-phthalaldehyde-specific IgG1, and OVA-specific serum IgE were found in o-phthalaldehyde-treated mice. Based on emerging incidences of bronchial asthma in hospital workers exposed to o-phthalaldehyde,^25^ another study evaluated the respiratory sensitization potential of o-phthalaldehyde following nose-only inhalation exposure in female C57Bl/6 mice.^26^ The study demonstrated that inhalation exposure to 500 ppb or greater o-phthalaldehyde resulted in o-phthalaldehyde-specific IgG1. o-Phthalaldehyde-specific IgE was not detected in the exposed mice. Cytokine gene expression and phenotyping of the lymphocyte cell population in the respiratory mucosa and draining lymph nodes indicated that o-phthalaldehyde has the potential to cause respiratory sensitization in mice. A study by Katagiri et al.^27^ investigated the potential neurotoxic effects of o-phthalaldehyde in female Wistar rats. The rats were exposed to 100 or 200 ppb o-phthalaldehyde by whole-body inhalation 5 days per week for 4 weeks. Dopamine levels were significantly decreased (approximately 50%) in the cerebrum but not in the other regions of the brain.

### Humans

Since its introduction to the market in the United States in 1999 for use as a high-level disinfectant, numerous case reports have associated o-phthalaldehyde with a variety of adverse health effects. Some of the unintentional human health effects reported by patients directly exposed to o-phthalaldehyde are discoloration of the oral and esophageal mucosa,^28^ and chemical burning of the esophagus.^29^ Four bladder cancer patients undergoing urologic procedures experienced nine episodes of anaphylactic shock that included urticaria, angioedema, and laryngeal edema.^30^ Skin testing of these patients strongly confirmed the role of o-phthalaldehyde in the observed anaphylactic reactions. In another report, anaphylaxis was reported in three patients following a laryngoscopic procedure; detection of o-phthalaldehyde-specific IgE in serum and in vitro histamine release tests identified o-phthalaldehyde as the allergen.^31^

A number of health problems have been reported by healthcare workers routinely using o-phthalaldehyde in occupational settings for cleaning endoscopes and devices for surgical procedures. Very low levels of o-phthalaldehyde have been reported to cause skin, eye, and respiratory symptoms. Cases of bronchial asthma and contact dermatitis associated with occupational exposures to o-phthalaldehyde have been frequently reported.^25,32,33^ In a study investigating adverse health effects in 70 healthcare workers in hospital endoscopy units using o-phthalaldehyde, 17 workers were diagnosed with contact dermatitis, occupational asthma, or eye irritation.^34^ A urology resident developed facial discoloration after a cystoscopy performed using o-phthalaldehyde-disinfected instruments.^35^ In contrast to these reports, the Health Hazard Evaluation Program run by the CDC and NIOSH did not find any significant evidence of skin irritation, skin discoloration, or symptoms of unusual shortness of breath in 74 o-phthalaldehyde-exposed workers when evaluated postshift for symptoms and compared to the non-o-phthalaldehyde exposed group of workers.^16^

## Reproductive and Developmental Toxicity

No information regarding the reproductive or developmental toxicity of o-phthalaldehyde in experimental animals or humans was found in the literature.

## Carcinogenicity

No information on the carcinogenicity of o-phthalaldehyde in experimental animals or humans was found in a review of the literature.

## Genetic Toxicity

No published reports on the genotoxicity of o-phthalaldehyde were identified in a search of the literature; however, in a summary of an industry-sponsored study, negative results were reported for o-phthalaldehyde (99.7% pure), tested over a concentration range of 1 to 30 µg/mL, in the HGPRT gene mutation assay in Chinese hamster ovary cells, with and without exogenous metabolic activation from rat liver S9 mix.^36^

## Study Rationale and Design

o-Phthalaldehyde was nominated by NIOSH to NTP for toxicological characterization based on its increasing use in sterilization of dental and medical equipment and due to lack of adequate and publicly available toxicologic data. Furthermore, human case reports in the literature document incidences of skin and respiratory system sensitization following occupational exposure to o-phthalaldehyde. o-Phthalaldehyde was also of interest because of its promotion as a safe alternative to the widely used disinfectant glutaraldehyde, a known skin and respiratory system sensitizer.

This toxicity report describes the results of toxicity studies in which Sprague Dawley rats and B6C3F1/N mice were exposed to o-phthalaldehyde by whole-body inhalation for 3 months. Inhalation was chosen as the route of exposure for these studies because inhalation is a major route of human exposure. The exposure concentrations for the 3-month studies were 0, 0.44, 0.88, 1.75, 3.5, and 7.0 ppm o-phthalaldehyde. The highest exposure concentration was selected based on NTP evaluations of the maximum achievable concentration without aerosolization (MACWA) under normal chamber environmental specifications. The lowest concentration was similar to the experimental limit of quantitation for the online monitor used in these studies. Although a lower limit of quantitation may have been achievable using this online monitor or available offline methods, exposure of animals to lower concentrations was not feasible under the conditions of these studies due to reactivity of the aldehyde moieties of o-phthalaldehyde with amines resulting from the presence of animals.