# Appendix H Sentinel Animal Program

## H.1 Methods

Rodents used in the National Toxicology Program are produced in optimally clean facilities to eliminate potential pathogens that may affect study results. The Sentinel Animal Program is part of the periodic monitoring of animal health that occurs during the toxicologic evaluation of test compounds. Under this program, the disease state of the rodents is monitored via sera or feces from extra (sentinel) or dosed animals in the study rooms. The sentinel animals and the study animals are subject to identical environmental conditions. Furthermore, the sentinel animals come from the same production source and weanling groups as the animals used for the studies of test compounds.

Blood samples were collected from each animal and allowed to clot, and the serum was separated. All samples were processed appropriately and evaluated for the presence of pathogens. Samples were tested in-house or sent to the Research Animal Diagnostic Laboratory (RADIL), University of Missouri (Columbia, MO). The laboratory methods and agents for which testing was performed are tabulated below; the times at which samples were collected during the studies are also listed.

Blood was collected from five male and five female rats and mice per time point during the 3-month studies.

Table H-1 Laboratory Methods and Agents Tested for in the Sentinel Animal Program

Method/Test | Time of Collection
Rats
ELISA
Mycoplasma pulmonis | 2 weeks
Pneumonia virus of mice (PVM) | 2 weeks
Rat coronavirus/sialodacryoadenitis virus (RCV/SDA) | 2 weeks
Rat parvovirus | 2 weeks
Sendai | 2 weeks
Multiplex Fluorescent Immunoassay
Kilham rat virus | Study termination
M. pulmonis | Study termination
Parvo NS-1 | Study termination
PVM | Study termination
RCV/SDA | Study termination
Rat minute virus | Study termination
Rat parvovirus | Study termination
Rat Theiler’s murine encephalomyelitis virus (TMEV)-like virus | Study termination
Sendai | Study termination
TMEV | Study termination
Toolan’s H-1 virus | Study termination
Mice
ELISA
Mouse hepatitis virus (MHV) | 2 weeks
Mouse parvovirus | 2 weeks
M. pulmonis | 2 weeks
PVM | 2 weeks
Sendai | 2 weeks
TMEV | 2 weeks
Multiplex Fluorescent Immunoassay
Ectromelia virus | Study termination
Epizootic diarrhea of infant mice | Study termination
Lymphocytic choriomeningitis virus | Study termination
M. pulmonis | Study termination
MHV | Study termination
Mouse norovirus | Study termination
Parvo NS-1 | Study termination
Mouse parvovirus | Study termination
Minute virus of mice | Study termination
PVM | Study termination
Reovirus | Study termination
TMEV | Study termination
Sendai | Study termination

## H.2 Results

All test results were negative.