# Appendix F Chemical Characterization and Generation of Chamber Concentrations

## F.1 Procurement and Characterization of o-Phthalaldehyde

o-Phthalaldehyde was obtained from MP Biomedicals, LLC (Solon, OH), in one lot (8674J) that was used during the 3-month studies. Identity and purity analyses were conducted by the study laboratory at Battelle Toxicology Northwest (Richland, WA) and by the analytical chemistry laboratory at Chemir Analytical Services (Maryland Heights, MO). Reports on analyses performed in support of the o-phthalaldehyde studies are on file at the National Institute of Environmental Health Sciences.

Lot 8674J of the chemical, a pale-yellow, coarse, crystalline material, was identified as o-phthalaldehyde by the study laboratory using infrared (IR) spectroscopy and by the analytical chemistry laboratory using Fourier transform IR and proton nuclear magnetic resonance (NMR) spectroscopy. All spectra were consistent with the structure of o-phthalaldehyde. Representative IR and NMR spectra are presented in Figure F-1 and Figure F-2.

The analytical chemistry laboratory determined the moisture content of lot 8674J using Karl Fischer titration and elemental analyses for carbon, hydrogen, nitrogen, and sulfur using inductively coupled plasma/optical emission spectroscopy. The study laboratory determined the purity of lot 8674J directly as well as relative to a commercial o-phthalaldehyde standard using gas chromatography (GC) with flame ionization detection (FID), and GC with mass spectrometry (MS) for identification of impurities.

For lot 8674J, Karl Fischer titration indicated approximately 0.12% water; elemental analyses for carbon and hydrogen were in agreement with the theoretical values for o-phthalaldehyde. GC/FID by system A (Table F-1) indicated one major peak that was 99% of the total peak area and three impurities that were each over 0.1% of the total peak area, with a combined total of approximately 1% of the total peak area. Two of the impurities were tentatively identified as toluene and phthalide by comparison of GC retention times to a chromatogram obtained from a standard solution containing possible impurities or degradation products that included toluene, phthalide, benzaldehyde, phthalan, N-hydroxyphthalimide, naphthalene, isophthalaldehyde, and terepthaldicarboxaldehyde. The third peak was not identified. GC/MS by system B indicated that the phthalide peak also contained phthalic acid, which eluted at the same retention time. Different GC columns of varying polarity with FID were used but failed to resolve these two compounds. To ensure the absence of certain degradation products, GC/FID by system A was used to determine the presence of acetonitrile, GC/MS by system B was used for chloroform, and high-performance liquid chromatography with ultraviolet detection (HPLC/UV) was used for 2-carboxybenzaldehyde. Acetonitrile and chloroform were less than 0.1%, and 2-carboxybenzaldehyde was approximately 0.4% by weight. The overall purity of lot 8674J was determined to be greater than 99%. The purity relative to the commercial standard was greater than 99.7%.

To ensure stability, the test chemical was stored refrigerated in the original sealed plastic containers. Periodic reanalyses of the bulk chemical were performed during the 3-month studies using GC/FID by system A, GC/MS by system B, and HPLC/UV and no degradation of the test chemical occurred.

## F.2 Vapor Generation and Exposure System

A diagram of the vapor generation and delivery system used in the 3-month studies is shown in Figure F-3. o-Phthalaldehyde vapor was generated from a flask heated with a heating mantle, purged by a heated nitrogen flow entering above the flask area, blended with heated dilution air to obtain the vapor concentration desired, and transported into a distribution manifold located above the generator. Vapor concentration was determined by the reservoir temperature, nitrogen flow rate, and dilution air flow rate. Pressure in the distribution manifold was fixed to ensure constant flows through the manifold and into the chambers.

Due to the high boiling point of o-phthalaldehyde, all vapor transport lines and the on-line GC transport sample line of the 7.0 ppm chambers were heated above the minimum temperature needed to transport vapor without condensation. Individual Teflon^®^-delivery lines carried the vapor from the distribution manifold to three-way exposure valves at the chamber inlets. The exposure valves diverted vapor from the metering valves to exposure chamber exhaust until the generation system stabilized and exposure could proceed; an additional 60 minutes was added to the prestart stabilization time to purge residual toluene present in the test chemical to less than 1% before exposures began. To initiate exposure, the chamber exposure valves were rotated to allow the vapor to flow to each chamber exposure duct where it was diluted with conditioned chamber air to achieve the desired exposure concentration.

The study laboratory designed the inhalation exposure chamber (Harford Systems Division of Lab Products, Inc., Aberdeen, MD) so that uniform vapor concentrations could be maintained throughout the chamber with the catch pans in place. The total active mixing volume of each chamber was 1.7 m^3^. A small particle detector (Model 3022A; TSI Inc., St. Paul, MN) was used with and without animals in the exposure chambers to ensure that o-phthalaldehyde vapor, and not aerosol, was produced. No particle counts above the minimum resolvable level (approximately 200 particles/cm^3^) were detected.

## F.3 Vapor Concentration Monitoring

Summaries of the chamber vapor concentrations are given in Table F-2. Concentrations of o-phthalaldehyde in exposure chambers were monitored by an on-line GC/FID by system C (Table F-1). Samples were drawn from all exposure and control chambers approximately every 20 minutes during each exposure period using Hasteloy-C stream-select and gas-sampling valves (VALCO Instruments Company, Houston, TX) in a separate, heated oven. The sampling lines composing the sample loop were made from Teflon^®^ tubing and were connected to the exposure chamber relative humidity sampling lines near the gas chromatograph. A vacuum regulator maintained a constant vacuum in the sample loop to compensate for variations in sample line pressure. An in-line flow meter between the vacuum regulator and the gas chromatograph allowed digital measurement of sample flow.

The on-line gas chromatograph was checked throughout the day for instrument drift against an on-line standard vapor of o-phthalaldehyde in nitrogen supplied by a standard generator (Kin-Tek; Precision Calibration Systems, La Marque, TX). The on-line gas chromatograph was checked before the start of each exposure day and after every tenth sample throughout the exposure period. The on-line gas chromatograph was calibrated prior to the start of the study and at least monthly by a comparison of chamber concentration data to data from grab samples that were collected with adsorbent gas sampling tubes containing silica gel (ORBO-52™; Supelco, Bellefonte, PA), extracted with acetonitrile containing α-terpineol as an internal standard, and analyzed using an off-line GC/FID system (system D). Originally, the grab samples were located within the whole body exposure chambers; however, after animals were transferred into the chambers, ammonia produced by the action of fecal bacteria on urine^37^ caused inaccurate measurements of exposure concentration; sampling tubes were moved within the inlet lines. Additional samples were collected from the on-line standard generator to bracket concentrations found in the exposure chambers. The off-line gas chromatograph was calibrated with gravimetrically prepared standards of o-phthalaldehyde and the internal standard (α-terpineol) in acrylonitrile.

## F.4 Chamber Atmosphere Characterization

Buildup and decay rates for chamber vapor concentrations were determined with and without animals present in the chambers. At a chamber airflow rate of 15 air changes per hour, the theoretical value for the time to achieve 90% of the target concentration after the beginning of vapor generation (T_90_) and the time for the chamber concentration to decay to 10% of the target concentration after vapor generation was terminated (T_10_) was approximately 9.2 minutes. For rats and mice in the 3-month studies, T_90_ values ranged from 15 to 21 minutes without animals present and from 24 to 35 minutes with animals; T_10_ values ranged from 10 to 18 minutes without animals present and from 14 to 39 minutes with animals. A T_90_ value of 17 minutes was used for these studies.

The uniformity of vapor concentration in the inhalation exposure chambers without animals was evaluated before each of the studies began; in addition, concentration uniformity with animals present in the chambers was measured once during the 3-month studies. The vapor concentration was measured using the on-line GC/FID system (system C, Table F-1). The automatic 12-port sample valve was disabled to allow continuous monitoring from a single input line. Samples were collected from 12 positions in each chamber. Chamber concentration uniformity was maintained throughout the studies.

The persistence of o-phthalaldehyde in the chambers after vapor delivery ended was determined by monitoring the vapor concentration overnight in the 7.0 ppm chamber without and with animals present in the chambers. The concentration decreased to 1% of the target concentration within 128 minutes without animals present and 279 minutes with animals present.

Stability studies of the test chemical were performed by the study laboratory on the distribution line and 7.0 and 0.44 ppm exposure chambers without animals present and on the 3.5 and 0.44 ppm exposure chambers with animals present. Samples were collected with two adsorbent tubes in series [ORBO-52^TM^ (silica gel) and ORBO-32^TM^ (activated coconut charcoal); Supelco, Bellefone, PA] during the first and last hours of generation, extracted with acetonitrile (internal standard, α-terpineol) and analyzed using GC/FID by system A. Samples were also collected from the generator reservoir. The presence of chloroform, acetonitrile, and 2-carboxybenzaldehyde in the exposure atmosphere was investigated using samples collected on ORBO-52^TM^ tubes by GC/FID by system A (acetonitrile), system B (chloroform), or HPLC/UV (2-carboxybenzaldehyde). These studies indicated that the o-phthalaldehyde test chemical was stable for 1 day.

Table F-1 Gas Chromatography Systems Used in the Inhalation Studies of o-Phthalaldehyde^a^

Detection System | Column | Carrier Gas | Oven Temperature Program
System A
Flame ionization | DB 624 Megabore, 30 m × 530 µm, 3.0 µm film (J&W Scientific, Folsom, CA) | Helium at 12 psi | 35°C for 5 minutes, then 8°C/minute to 240°C, held for 2 minutes
System B
Mass spectrometry Electron impact with selected ion monitoring | RTX^®^-5, 30 m × 320 µm, 1.0 µm film (Restek, Bellefonte, PA) | Helium at 6 psi head pressure | 38°C for 5 minutes, then 8°C/minute to 320°C, held for 2 minutes
System C
Flame ionization | DB 5, 15 m × 530 µm, 1.5 µm film (J&W Scientific) | Nitrogen at 25 mL/minute | Isothermal at 140°C
System D
Flame ionization | DB 624 Megabore, 30 m × 530 µm, 3.0 µm film (J&W Scientific) | Helium at 12 psi head pressure | 65°C for 1 minute, then 15°C/minute to 210°C, held for 2 minutes

^a^ The gas chromatographs and mass spectrometer were manufactured by Agilent Technologies, Inc. (Santa Clara, CA).

Table F-2 Summary of Chamber Concentrations in the Three-month Inhalation Studies of o-Phthalaldehyde

| Target Concentration (ppm) | Total Number of Readings | Average Concentration^a^ (ppm)
Rat Chambers
| 0.44 | 989 | 0.43 ± 0.04
| 0.88 | 982 | 0.86 ± 0.07
| 1.75 | 990 | 1.69 ± 0.14
| 3.5 | 1,013 | 3.4 ± 0.4
| 7.0 | 127 | 7.1 ± 0.5
Mouse Chambers
| 0.44 | 1,020 | 0.43 ± 0.04
| 0.88 | 1,013 | 0.86 ± 0.07
| 1.75 | 1,021 | 1.69 ± 0.13
| 3.5 | 1,044 | 3.4 ± 0.4
| 7.0 | 68 | 6.9 ± 0.6

^a^ Mean ± standard deviation.

Figure F-1

Infrared Absorption Spectrum of o-Phthalaldehyde

Figure F-2

Proton Nuclear Magnetic Resonance Spectrum of o-Phthalaldehyde

Figure F-3

Schematic of the Vapor Generation and Delivery System in the Inhalation Studies of o-Phthalaldehyde