# Appendix E Genetic Toxicology

Table E-1 Mutagenicity of o-Phthalaldehyde in Bacterial Tester Strains^a^

Strain | Dose (μg/plate) | Without S9 | Without S9 | With 10% rat S9 | With 10% rat S9
TA100
| 0 | 98 ± 1 | 104 ± 4 | 116 ± 7 | 145 ± 4
| 0.5 | | 100 ± 11
| 1 | | 108 ± 3
| 5 | 124 ± 2 | 110 ± 8
| 10 | 147 ± 8 | 155 ± 5 | 139 ± 5
| 25 | 191 ± 15 | 224 ± 2 | 129 ± 3
| 50 | 58 ± 6 | | 127 ± 3 | 140 ± 2
| 100 | 0 ± 0 | | 152 ± 3 | 157 ± 2
| 200 | | | 162 ± 15 | 136 ± 3
| 300 | | | | 62 ± 8
| 400 | | | | 1 ± 1
Trial summary | | Positive | Positive | Negative | Negative
Positive control^b^ | | 443 ± 15 | 599 ± 29 | 771 ± 34 | 680 ± 15
TA98
| 0 | 40 ± 4 | 37 ± 1 | 41 ± 2 | 46 ± 4
| 0.5 | 40 ± 4
| 1 | 47 ± 3
| 5 | 55 ± 1 | 40 ± 1
| 10 | 53 ± 0 | 39 ± 1 | 36 ± 3 | 62 ± 3
| 25 | 19 ± 3 | 31 ± 5 | 37 ± 3 | 49 ± 2
| 50 | | 43 ± 4 | 32 ± 2 | 61 ± 3
| 100 | | 0 ± 0 | 27 ± 1 | 55 ± 4
| 200 | | | 28 ± 2 | 25 ± 4
Trial summary | | Negative | Negative | Negative | Negative
Positive control | | 560 ± 36 | 564 ± 11 | 1,061 ± 146 | 861 ± 71
Escherichia coli WP2 uvrA/pKM101
| 0 | 176 ± 15 | 228 ± 20 | 205 ± 8 | 194 ± 22
| 0.5 | | 230 ± 6
| 1 | | 254 ± 20
| 5 | 175 ± 12 | 244 ± 7
| 10 | 200 ± 5 | 285 ± 8 | 248 ± 8 | 194 ± 14
| 25 | 207 ± 4 | 77 ± 7 | 241 ± 15 | 194 ± 25
| 50 | 252 ± 8 | | 245 ± 13 | 198 ± 5
| 100 | 81 ± 13 | | 251 ± 8 | 224 ± 28
| 200 | | | 264 ± 14 | 223 ± 9
Trial summary | | Negative | Negative | Negative | Negative
Positive control | | 799 ± 52 | 667 ± 29 | 641 ± 25 | 913 ± 64

^a^ Study was performed at SITEK Research Laboratories. Data are presented as revertants/plate (mean ± standard error) from three plates. 0 μg/plate was the solvent (dimethyl sulfoxide) control.

^b^ The positive controls in the absence of metabolic activation were sodium azide (TA100), 2-nitrofluorine (TA98), and methyl methanesulfonate (E. coli). The positive control for metabolic activation with all strains was 2-aminoanthracene.

Table E-2 Frequency of Micronuclei in Peripheral Blood Erythrocytes of Rats Following Exposure to o-Phthalaldehyde by Inhalation for Three Months^a^

Concentration (ppm) | Number of Rats with Erythrocytes Scored | Micronucleated PCEs/ 1,000 PCEs^b^ | P Value^c^ | Micronucleated NCEs/ 1,000 NCEs^b^ | P Value^d^ | PCEs^b^ (%) | P Value^c^
Male
Air^e^ | 5 | 0.72 ± 0.08 | | 0.10 ± 0.02 | | 0.818 ± 0.05
o-Phthalaldehyde
0.44 | 5 | 0.71 ± 0.10 | 0.5195 | 0.09 ± 0.01 | 0.7466 | 0.988 ± 0.09 | 0.102
0.88 | 5 | 0.77 ± 0.06 | 0.4043 | 0.08 ± 0.02 | 0.8261 | 0.990 ± 0.06 | 0.120
1.75 | 5 | 0.90 ± 0.09 | 0.0916 | 0.08 ± 0.01 | 0.8567 | 0.898 ± 0.03 | 0.124
3.5 | 2 | 0.93 ± 0.02 | –^f^ | 0.08 ± 0.03 | – | 1.249 ± 0.18 | –
| | P = 0.043^g^ | | P = 0.905^g^ | | P = 0.526^g^
Female
Air | 5 | 0.53 ± 0.05 | | 0.13 ± 0.03 | | 0.811 ± 0.09
o-Phthalaldehyde
0.44 | 5 | 0.65 ± 0.12 | 0.2322 | 0.12 ± 0.03 | 1.0000 | 0.784 ± 0.05 | 1.000
0.88 | 5 | 0.63 ± 0.09 | 0.2785 | 0.08 ± 0.01 | 1.0000 | 0.837 ± 0.08 | 1.000
1.75 | 5 | 0.75 ± 0.13 | 0.0915 | 0.07 ± 0.01 | 1.0000 | 0.838 ± 0.11 | 1.000
3.5 | 5 | 0.77 ± 0.11 | 0.0729 | 0.06 ± 0.01 | 1.0000 | 0.729 ± 0.08 | 0.663
| | P = 0.046^g^ | | P = 0.989^h^ | | P = 0.442^g^

^a^ Study was performed at ILS, Inc. The detailed protocol is presented by Witt et al.^53^ PCE = polychromatic erythrocyte; NCE = normochromatic erythrocyte.

^b^ Mean ± standard error.

^c^ Pairwise comparison with the chamber control group; exposed group values are significant at P ≤ 0.025 by William’s test.

^d^ Pairwise comparison with the chamber control group; exposed group values are significant at P ≤ 0.025 by William’s test (males) or Dunn’s test (females).

^e^ Chamber control.

^f^ Small sample size precludes statistical analysis.

^g^ Exposure concentration-related trend; significant at P ≤ 0.025 by linear regression.

^h^ Exposure concentration-related trend; significant at P ≤ 0.025 by Jonckheere’s test.

Table E-3 Frequency of Micronuclei in Peripheral Blood Erythrocytes of Mice Following Exposure to o-Phthalaldehyde by Inhalation for Three Months^a^

Concentration (ppm) | Number of Rats with Erythrocytes Scored | Micronucleated PCEs/ 1,000 PCEs^b^ | P Value^c^ | Micronucleated NCEs/ 1,000 NCEs^b^ | P Value^d^ | PCEs^b^ (%) | P Value^c^
Male
Air^e^ | 5 | 2.31 ± 0.17 | | 1.40 ± 0.02 | | 1.413 ± 0.03
o-Phthalaldehyde
0.44 | 5 | 2.02 ± 0.15 | 0.6297 | 1.40 ± 0.01 | 1.0000 | 1.251 ± 0.01 | 0.1137
0.88 | 5 | 2.16 ± 0.21 | 0.7169 | 1.35 ± 0.03 | 1.0000 | 1.446 ± 0.05 | 1.0000
1.75 | 5 | 2.25 ± 0.10 | 0.6720 | 1.29 ± 0.04 | 1.0000 | 1.378 ± 0.05 | 1.0000
3.5 | 5 | 3.24 ± 0.61 | 0.0289 | 1.44 ± 0.13 | 1.0000 | 1.521 ± 0.21 | 1.0000
| | P = 0.005^f^ | | P = 0.992^g^ | | P = 0.151^g^
Female
Air | 5 | 2.39 ± 0.19 | | 0.98 ± 0.02 | | 1.400 ± 0.16
o-Phthalaldehyde
0.44 | 5 | 2.06 ± 0.17 | 0.9680 | 0.99 ± 0.02 | 1.0000 | 1.323 ± 0.04 | 1.0000
0.88 | 5 | 1.85 ± 0.08 | 0.9873 | 1.02 ± 0.02 | 0.3124 | 1.398 ± 0.06 | 1.0000
1.75 | 5 | 1.88 ± 0.13 | 0.9918 | 0.98 ± 0.02 | 1.0000 | 1.460 ± 0.04 | 1.0000
3.5 | 5 | 1.79 ± 0.12 | 0.9942 | 0.98 ± 0.03 | 1.0000 | 1.920 ± 0.11 | 0.0351
| | P=0.989^f^ | | P=0.424^g^ | | P=0.001^g^

^a^ Study was performed at ILS, Inc. The detailed protocol is presented by Witt et al.^53^ PCE = polychromatic erythrocyte; NCE = normochromatic erythrocyte.

^b^ Mean ± standard error.

^c^ Pairwise comparison with the chamber control group; exposed group values are significant at P ≤ 0.025 by William’s test..

^d^ Pairwise comparison with the chamber control group; exposed group values are significant at P ≤ 0.025 by Dunn’s test.

^e^ Chamber control.

^f^ Exposure concentration-related trend; significant at P ≤ 0.025 by linear regression.

^g^ Exposure concentration-related trend; significant at P ≤ 0.025 by Jonckheere’s test.