# Appendix D Reproductive Tissue Evaluations

Table D-1 Summary of Reproductive Tissue Evaluations for Male Rats in the Three-month Inhalation Study of o-Phthalaldehyde^a^

| Chamber Control | 0.44 ppm | 0.88 ppm | 1.75 ppm
n | 10 | 10 | 10 | 10
Weights (g)
Necropsy body wt | 409 ± 4 | 377 ± 6** | 350 ± 5** | 309 ± 9**
L. Cauda epididymis | 0.2555 ± 0.0092 | 0.2697 ± 0.0109 | 0.2140 ± 0.0103** | 0.1956 ± 0.0072**
L. Epididymis | 0.6692 ± 0.0100 | 0.6559 ± 0.0197 | 0.5721 ± 0.0254** | 0.5405 ± 0.0133**
L. Testis | 2.0070 ± 0.0294 | 1.9794 ± 0.0590 | 1.7603 ± 0.1211* | 1.7549 ± 0.0316*
Spermatid measurements
Spermatid heads (10^6^/testis) | 236.31 ± 24.29 | 295.95 ± 23.57 | 183.59 ± 30.05 | 280.25 ± 17.80
Spermatid heads (10^6^/g testis) | 118.57 ± 13.03 | 148.74 ± 10.06 | 98.55 ± 14.70 | 160.29 ± 11.14
Epididymal spermatozoal measurements
Sperm motility (%) | 83.1 ± 1.5 | 75.2 ± 1.5** | 67.1 ± 8.1** | 65.6 ± 2.5**
Sperm (10^6^/cauda epididymis) | 81.19 ± 2.44 | 87.24 ± 6.47 | 69.88 ± 10.56 | 66.68 ± 5.57
Sperm (10^6^/g cauda epididymis) | 321 ± 13 | 325 ± 22 | 314 ± 48 | 340 ± 25

* Significantly different (P ≤ 0.05) from the chamber control group by Williams’ test.

** Significantly different (P ≤ 0.01) from the chamber control group by Williams’ (body or tissue weights) or Shirley’s (motility) test.

^a^ Data are presented as mean ± standard error. Differences from the chamber control group are not significant by Dunn’s test (spermatid measurements, sperm per cauda epididymis, and sperm per gram cauda epididymis).

Table D-2 Summary of Reproductive Tissue Evaluations for Male Mice in the Three-month Inhalation Study of o-Phthalaldehyde^a^

| Chamber Control | 0.44 ppm | 0.88 ppm | 1.75 ppm
n | 10 | 10 | 10 | 10
Weights (g)
Necropsy body wt | 35.6 ± 0.9 | 29.5 ± 0.4** | 27.2 ± 0.4** | 25.8 ± 0.3**
L. Cauda epididymis | 0.0157 ± 0.0013 | 0.0140 ± 0.0010 | 0.0143 ± 0.0012 | 0.0147 ± 0.0014
L. Epididymis | 0.0443 ± 0.0021 | 0.0420 ± 0.0030 | 0.0359 ± 0.0025 | 0.0413 ± 0.0025
L. Testis | 0.1080 ± 0.0023 | 0.1055 ± 0.0015 | 0.1013 ± 0.0019 | 0.1029 ± 0.0021
Spermatid measurements
Spermatid heads (10^6^/testis) | 21.65 ± 2.10 | 22.26 ± 2.68 | 23.88 ± 1.28 | 18.73 ± 1.61
Spermatid heads (10^6^/g testis) | 199.4 ± 17.2 | 210.0 ± 24.0 | 236.1 ± 12.5 | 182.7 ± 15.8
Epididymal spermatozoal measurements
Sperm motility (%) | 74.7 ± 8.4 | 69.5 ± 7.8* | 68.8 ± 7.7** | 41.8 ± 9.6**
Sperm (10^6^/cauda epididymis) | 8.52 ± 0.48 | 7.79 ± 0.44 | 6.89 ± 0.90 | 7.26 ± 0.48
Sperm (10^6^/g cauda epididymis) | 573 ± 53 | 571 ± 41 | 510 ± 67 | 542 ± 68

* Significantly different (P ≤ 0.05) from the chamber control group by Shirley’s test.

** Significantly different (P ≤ 0.01) from the chamber control group by Williams’ (body weights) or Shirley’s (motility) test.

^a^ Data are presented as mean ± standard error. Differences from the chamber control group are not significant by Dunnett’s test (tissue weights) or Dunn’s test (spermatid measurements, sperm per cauda epididymis, and sperm per gram cauda epididymis).