# Appendix C Organ Weights and Organ Weight-to-Body-Weight Ratios

Table C-1 Organ Weights and Organ-Weight-to-Body-Weight Ratios for Rats in the Three-month Inhalation Study of o-Phthalaldehyde^a^

| Chamber Control | 0.44 ppm | 0.88 ppm | 1.75 ppm | 3.5 ppm
Male
n | 10 | 10 | 10 | 10 | 3
Necropsy body wt | 409 ± 4 | 377 ± 6** | 350 ± 5** | 309 ± 9** | 222 ± 15**
Heart
Absolute | 1.37 ± 0.03 | 1.30 ± 0.03* | 1.23 ± 0.02** | 1.12 ± 0.03** | 0.92 ± 0.04**
Relative | 3.36 ± 0.05 | 3.44 ± 0.05 | 3.50 ± 0.05 | 3.63 ± 0.07** | 4.18 ± 0.21**
R. Kidney
Absolute | 1.31 ± 0.03 | 1.21 ± 0.03* | 1.15 ± 0.03** | 1.05 ± 0.03** | 0.82 ± 0.03**
Relative | 3.21 ± 0.07 | 3.21 ± 0.06 | 3.28 ± 0.07 | 3.40 ± 0.04* | 3.71 ± 0.18**
Liver
Absolute | 12.17 ± 0.25 | 11.11 ± 0.32* | 10.53 ± 0.33** | 9.68 ± 0.45** | 6.93 ± 0.19**
Relative | 29.82 ± 0.64 | 29.45 ± 0.71 | 30.05 ± 0.77 | 31.20 ± 0.78 | 31.44 ± 2.07
Lung
Absolute | 2.16 ± 0.10 | 2.02 ± 0.07 | 2.02 ± 0.14 | 2.17 ± 0.10 | 2.00 ± 0.14
Relative | 5.31 ± 0.27 | 5.36 ± 0.19 | 5.75 ± 0.38 | 7.07 ± 0.40** | 9.06 ± 0.75**
R. Testis
Absolute | 2.014 ± 0.033 | 1.956 ± 0.052 | 1.772 ± 0.118* | 1.744 ± 0.054* | 1.607 ± 0.041**
Relative | 4.932 ± 0.077 | 5.192 ± 0.129 | 5.059 ± 0.329 | 5.649 ± 0.155* | 7.274 ± 0.321**
Thymus
Absolute | 0.348 ± 0.014 | 0.314 ± 0.019 | 0.298 ± 0.012* | 0.241 ± 0.017** | 0.154 ± 0.009**
Relative | 0.851 ± 0.034 | 0.834 ± 0.055 | 0.851 ± 0.033 | 0.779 ± 0.051 | 0.704 ± 0.089
Female
n | 10 | 10 | 10 | 10 | 8
Necropsy body wt | 239 ± 5 | 238 ± 5 | 230 ± 3 | 214 ± 5** | 205 ± 6**
Heart
Absolute | 0.89 ± 0.02 | 0.88 ± 0.02 | 0.90 ± 0.04 | 0.82 ± 0.02 | 0.86 ± 0.02
Relative | 3.73 ± 0.06 | 3.71 ± 0.06 | 3.93 ± 0.18 | 3.85 ± 0.08 | 4.23 ± 0.13**
R. Kidney
Absolute | 0.83 ± 0.02 | 0.83 ± 0.02 | 0.81 ± 0.02 | 0.73 ± 0.01** | 0.72 ± 0.02**
Relative | 3.47 ± 0.08 | 3.49 ± 0.05 | 3.51 ± 0.08 | 3.42 ± 0.06 | 3.52 ± 0.05
Liver
Absolute | 6.98 ± 0.15 | 7.13 ± 0.28 | 6.79 ± 0.32 | 6.74 ± 0.24 | 7.06 ± 0.26
Relative | 29.19 ± 0.43 | 29.88 ± 0.65 | 29.53 ± 1.31 | 31.54 ± 0.66 | 34.54 ± 0.80**
Lung
Absolute | 1.78 ± 0.07 | 1.66 ± 0.03 | 1.67 ± 0.07 | 1.79 ± 0.08 | 1.75 ± 0.07
Relative | 7.42 ± 0.26 | 7.01 ± 0.14 | 7.30 ± 0.34 | 8.46 ± 0.48 | 8.61 ± 0.44
Thymus
Absolute | 0.274 ± 0.015 | 0.226 ± 0.013* | 0.246 ± 0.010* | 0.173 ± 0.013** | 0.154 ± 0.009**
Relative | 1.139 ± 0.051 | 0.951 ± 0.052 | 1.068 ± 0.036 | 0.802 ± 0.052** | 0.754 ± 0.039**

* Significantly different (P ≤ 0.05) from the chamber control group by Williams’ test.

** P ≤ 0.01.

^a^ Organ weights (absolute weights) and body weights are given in grams; organ-weight-to-body-weight ratios (relative weights) are given as mg organ weight/g body weight (mean ± standard error). Due to 100% mortality in rats exposed to 7.0 ppm, no data are available for this group.

Table C-2 Organ Weights and Organ-Weight-to-Body-Weight Ratios for Mice in the Three-month Inhalation Study of o-Phthalaldehyde^a^

| Chamber Control | 0.44 ppm | 0.88 ppm | 1.75 ppm | 3.5 ppm
Male
n | 10 | 10 | 10 | 10 | 5
Necropsy body wt | 35.6 ± 0.9 | 29.5 ± 0.4** | 27.2 ± 0.4** | 25.8 ± 0.3** | 21.6 ± 0.8**
Heart
Absolute | 0.15 ± 0.00 | 0.13 ± 0.00** | 0.13 ± 0.00** | 0.13 ± 0.00** | 0.12 ± 0.01**
Relative | 4.31 ± 0.10 | 4.41 ± 0.11 | 4.60 ± 0.04* | 4.88 ± 0.08** | 5.57 ± 0.20**
R. Kidney
Absolute | 0.29 ± 0.01 | 0.23 ± 0.00** | 0.21 ± 0.00** | 0.21 ± 0.00** | 0.19 ± 0.00**
Relative | 8.15 ± 0.15 | 7.74 ± 0.17 | 7.86 ± 0.10 | 8.02 ± 0.19 | 8.92 ± 0.17*
Liver
Absolute | 1.41 ± 0.05 | 1.07 ± 0.03** | 1.09 ± 0.02** | 1.03 ± 0.04** | 0.97 ± 0.05**
Relative | 39.55 ± 1.02 | 36.28 ± 1.03 | 40.14 ± 1.12 | 39.91 ± 1.64 | 44.96 ± 2.04*
Lung
Absolute | 0.20 ± 0.01 | 0.19 ± 0.00 | 0.19 ± 0.00 | 0.18 ± 0.00* | 0.19 ± 0.01
Relative | 5.65 ± 0.19 | 6.55 ± 0.16** | 7.03 ± 0.18** | 7.08 ± 0.10** | 8.64 ± 0.29**
R. Testis
Absolute | 0.110 ± 0.002 | 0.105 ± 0.002* | 0.104 ± 0.001* | 0.105 ± 0.002* | 0.084 ± 0.002**
Relative | 3.108 ± 0.071 | 3.563 ± 0.069** | 3.810 ± 0.069** | 4.060 ± 0.057** | 3.903 ± 0.104**
Thymus
Absolute | 0.041 ± 0.002 | 0.028 ± 0.003** | 0.026 ± 0.002** | 0.028 ± 0.002** | 0.020 ± 0.005**
Relative | 1.159 ± 0.041 | 0.933 ± 0.084 | 0.955 ± 0.064 | 1.089 ± 0.078 | 0.917 ± 0.199
Female
n | 10 | 10 | 10 | 10 | 6
Necropsy body wt | 29.8 ± 0.9 | 25.5 ± 0.3** | 23.3 ± 0.3** | 22.8 ± 0.4** | 20.7 ± 0.8**
Heart
Absolute | 0.14 ± 0.00 | 0.12 ± 0.00** | 0.12 ± 0.00** | 0.11 ± 0.00** | 0.13 ± 0.01**
Relative | 4.65 ± 0.10 | 4.72 ± 0.10 | 5.03 ± 0.08 | 4.98 ± 0.15 | 6.38 ± 0.62**
R. Kidney
Absolute | 0.20 ± 0.01 | 0.17 ± 0.01** | 0.16 ± 0.01** | 0.17 ± 0.00** | 0.17 ± 0.01**
Relative | 6.76 ± 0.23 | 6.76 ± 0.21 | 7.00 ± 0.16 | 7.49 ± 0.19* | 8.39 ± 0.07**
Liver
Absolute | 1.31 ± 0.04 | 1.12 ± 0.02** | 1.06 ± 0.03** | 1.01 ± 0.02** | 1.03 ± 0.05**
Relative | 43.97 ± 0.85 | 43.96 ± 1.04 | 45.62 ± 0.85 | 44.54 ± 0.96 | 49.88 ± 1.74**
Lung
Absolute | 0.21 ± 0.00 | 0.21 ± 0.01 | 0.19 ± 0.00* | 0.19 ± 0.00** | 0.21 ± 0.00
Relative | 7.07 ± 0.22 | 8.05 ± 0.20** | 8.35 ± 0.13** | 8.32 ± 0.18** | 10.31 ± 0.38**
Thymus
Absolute | 0.056 ± 0.003 | 0.043 ± 0.002** | 0.038 ± 0.003** | 0.040 ± 0.002** | 0.030 ± 0.004**
Relative | 1.898 ± 0.085 | 1.692 ± 0.091 | 1.641 ± 0.124 | 1.749 ± 0.088 | 1.433 ± 0.151*

* Significantly different (P ≤ 0.05) from the chamber control group by Williams’ or Dunnett’s test.

** P ≤ 0.01.

^a^ Organ weights (absolute weights) and body weights are given in grams; organ-weight-to-body-weight ratios (relative weights) are given as mg organ weight/g body weight (mean ± standard error). Due to 100% mortality in mice exposed to 7.0 ppm, no data are available for this group.