# Appendix B Clinical Pathology Results

Table B-1 Hematology and Clinical Chemistry Data for Rats in the Three-month Inhalation Study of o-Phthalaldehyde^a^

| Chamber Control | 0.44 ppm | 0.88 ppm | 1.75 ppm | 3.5 ppm | 7.0 ppm
Male
n
Day 3 | 10 | 10 | 10 | 10 | 10 | 9
Day 23 | 10 | 10 | 10 | 9 | 5 | 0
Week 14 | 10 | 10 | 10 | 10 | 3 | 0
Hematology
Hematocrit (spun) (%)
Day 3 | 41.4 ± 0.4 | 42.5 ± 0.4 | 42.1 ± 0.3 | 45.9 ± 0.7** | 48.9 ± 0.8** | 50.5 ± 0.5**
Day 23 | 45.1 ± 0.3 | 45.9 ± 0.5 | 47.1 ± 0.7* | 48.4 ± 0.5** | 55.9 ± 1.0** | –
Week 14 | 48.3 ± 0.4 | 48.8 ± 0.5 | 50.2 ± 0.4** | 49.6 ± 0.6* | 51.3 ± 1.1* | –
Packed cell volume (%)
Day 3 | 39.6 ± 0.4 | 40.6 ± 0.4 | 40.0 ± 0.4 | 44.1 ± 0.6** | 47.2 ± 0.9** | 49.5 ± 0.5**
Day 23 | 43.8 ± 0.3 | 44.2 ± 0.5 | 45.5 ± 0.6* | 47.1 ± 0.5** | 53.9 ± 1.1** | –
Week 14 | 46.4 ± 0.4 | 47.4 ± 0.4 | 49.1 ± 0.4** | 48.2 ± 0.5** | 50.3 ± 1.7* | –
Hemoglobin (g/dL)
Day 3 | 12.7 ± 0.1 | 13.1 ± 0.1 | 13.1 ± 0.1 | 14.4 ± 0.2** | 15.3 ± 0.3** | 16.2 ± 0.2**
Day 23 | 14.4 ± 0.1 | 14.5 ± 0.2 | 15.0 ± 0.2* | 15.5 ± 0.2** | 17.7 ± 0.3** | –
Week 14 | 15.6 ± 0.1 | 15.9 ± 0.1 | 16.3 ± 0.1** | 16.1 ± 0.2** | 17.0 ± 0.5** | –
Erythrocytes (10^6^/μL)
Day 3 | 6.03 ± 0.07 | 6.16 ± 0.06 | 6.23 ± 0.07 | 6.84 ± 0.11** | 7.42 ± 0.15** | 7.84 ± 0.11**
Day 23 | 7.19 ± 0.05 | 7.18 ± 0.07 | 7.52 ± 0.11* | 7.85 ± 0.08** | 9.16 ± 0.23** | –
Week 14 | 8.53 ± 0.08 | 8.62 ± 0.08 | 8.87 ± 0.09 | 8.71 ± 0.12 | 8.99 ± 0.27 | –
Reticulocytes (10^3^/μL)
Day 3 | 446 ± 10 | 413 ± 18 | 393 ± 17 | 451 ± 13 | 515 ± 17* | 507 ± 19*
Day 23 | 281 ± 15 | 255 ± 10 | 235 ± 13 | 265 ± 11 | 277 ± 28 | –
Week 14 | 193 ± 13 | 205 ± 9 | 185 ± 13 | 196 ± 11 | 270 ± 13 | –
Nucleated erythrocytes/100 leukocytes
Day 3 | 0.2 ± 0.1 | 0.2 ± 0.1 | 0.1 ± 0.1 | 0.2 ± 0.2 | 0.5 ± 0.3 | 0.6 ± 0.2
Day 23 | 0.0 ± 0.0 | 0.0 ± 0.0 | 0.0 ± 0.0 | 0.0 ± 0.0 | 0.0 ± 0.0 | –
Week 14 | 0.0 ± 0.0 | 0.0 ± 0.0 | 0.0 ± 0.0 | 0.0 ± 0.0 | 0.0 ± 0.0 | –
Mean cell volume (fL)
Day 3 | 65.7 ± 0.4 | 66.0 ± 0.6 | 64.3 ± 0.3 | 64.5 ± 0.5 | 63.6 ± 0.3** | 63.1 ± 0.6**
Day 23 | 61.0 ± 0.2 | 61.6 ± 0.5 | 60.5 ± 0.3 | 60.0 ± 0.2* | 58.9 ± 0.6** | –
Week 14 | 54.5 ± 0.5 | 55.0 ± 0.4 | 55.4 ± 0.7 | 55.3 ± 0.5 | 55.8 ± 0.3 | –
Mean cell hemoglobin (pg)
Day 3 | 21.1 ± 0.1 | 21.3 ± 0.2 | 21.0 ± 0.1 | 21.0 ± 0.1 | 20.7 ± 0.2 | 20.7 ± 0.2
Day 23 | 20.0 ± 0.1 | 20.2 ± 0.2 | 19.9 ± 0.1 | 19.8 ± 0.1 | 19.4 ± 0.2* | –
Week 14 | 18.3 ± 0.1 | 18.5 ± 0.1 | 18.4 ± 0.2 | 18.5 ± 0.2 | 18.9 ± 0.1 | –
Mean cell hemoglobin concentration (g/dL)
Day 3 | 32.1 ± 0.2 | 32.3 ± 0.2 | 32.7 ± 0.1 | 32.5 ± 0.1 | 32.5 ± 0.1 | 32.8 ± 0.1**
Day 23 | 32.8 ± 0.1 | 32.9 ± 0.1 | 32.9 ± 0.1 | 32.9 ± 0.1 | 32.9 ± 0.1 | –
Week 14 | 33.5 ± 0.1 | 33.6 ± 0.1 | 33.2 ± 0.2 | 33.4 ± 0.1 | 33.8 ± 0.1 | –
Platelets (10^3^/μL)
Day 3 | 1,112 ± 29 | 1,164 ± 30 | 1,170 ± 30 | 1,259 ± 45** | 1,328 ± 50** | 1,355 ± 85**
Day 23 | 975 ± 33 | 936 ± 10 | 941 ± 24 | 935 ± 19 | 786 ± 42** | –
Week 14 | 823 ± 23 | 781 ± 13 | 770 ± 22 | 703 ± 23** | 697 ± 51* | –
Leukocytes (10^3^/μL)
Day 3 | 14.58 ± 0.66 | 13.44 ± 1.04 | 13.56 ± 0.93 | 9.38 ± 0.83** | 8.89 ± 1.08** | 8.87 ± 0.69**
Day 23 | 12.02 ± 0.81 | 10.94 ± 0.44 | 11.14 ± 0.77 | 10.04 ± 0.68 | 7.98 ± 0.73** | –
Week 14 | 11.34 ± 0.49 | 11.81 ± 0.65 | 10.73 ± 0.74 | 9.27 ± 0.60* | 6.69 ± 0.30** | –
Segmented neutrophils (10^3^/μL)
Day 3 | 1.41 ± 0.12 | 1.33 ± 0.20 | 1.46 ± 0.16 | 1.12 ± 0.11 | 2.06 ± 0.50 | 3.28 ± 0.20**
Day 23 | 1.36 ± 0.20 | 1.38 ± 0.12 | 2.76 ± 0.57** | 2.30 ± 0.17** | 2.95 ± 0.34** | –
Week 14 | 1.35 ± 0.14 | 1.66 ± 0.11 | 2.05 ± 0.16** | 2.39 ± 0.13** | 2.42 ± 0.24** | –
Bands (10^3^/μL)
Day 3 | 0.00 ± 0.00 | 0.00 ± 0.00 | 0.00 ± 0.00 | 0.00 ± 0.00 | 0.00 ± 0.00 | 0.00 ± 0.00
Day 23 | 0.00 ± 0.00 | 0.00 ± 0.00 | 0.00 ± 0.00 | 0.00 ± 0.00 | 0.00 ± 0.00 | –
Week 14 | 0.00 ± 0.00 | 0.00 ± 0.00 | 0.00 ± 0.00 | 0.00 ± 0.00 | 0.00 ± 0.00 | –
Lymphocytes (10^3^/μL)
Day 3 | 12.92 ± 0.58 | 11.78 ± 0.82 | 11.81 ± 0.84 | 8.05 ± 0.83** | 6.58 ± 0.61** | 5.40 ± 0.69**
Day 23 | 10.45 ± 0.72 | 9.28 ± 0.42 | 8.14 ± 0.36* | 7.52 ± 0.64** | 4.80 ± 0.49** | –
Week 14 | 9.72 ± 0.39 | 9.87 ± 0.62 | 8.42 ± 0.66* | 6.67 ± 0.54** | 3.84 ± 0.46** | –
Monocytes (10^3^/μL)
Day 3 | 0.13 ± 0.03 | 0.16 ± 0.04 | 0.14 ± 0.03 | 0.07 ± 0.02 | 0.16 ± 0.10 | 0.07 ± 0.02
Day 23 | 0.09 ± 0.02 | 0.14 ± 0.02 | 0.10 ± 0.02 | 0.07 ± 0.02 | 0.06 ± 0.02 | –
Week 14 | 0.10 ± 0.02 | 0.06 ± 0.01 | 0.04 ± 0.01* | 0.07 ± 0.02 | 0.07 ± 0.03 | –
Basophils (10^3^/μL)
Day 3 | 0.028 ± 0.005 | 0.024 ± 0.003 | 0.028 ± 0.004 | 0.021 ± 0.004 | 0.010 ± 0.003** | 0.003 ± 0.002**
Day 23 | 0.021 ± 0.002 | 0.021 ± 0.002 | 0.024 ± 0.004 | 0.027 ± 0.004 | 0.002 ± 0.002* | –
Week 14 | 0.015 ± 0.005 | 0.024 ± 0.006 | 0.013 ± 0.004 | 0.011 ± 0.002 | 0.003 ± 0.003 | –
Eosinophils (10^3^/μL)
Day 3 | 0.11 ± 0.01 | 0.14 ± 0.02 | 0.12 ± 0.01 | 0.12 ± 0.02 | 0.08 ± 0.02 | 0.12 ± 0.04
Day 23 | 0.10 ± 0.01 | 0.12 ± 0.02 | 0.12 ± 0.01 | 0.12 ± 0.03 | 0.16 ± 0.09 | –
Week 14 | 0.17 ± 0.03 | 0.20 ± 0.03 | 0.21 ± 0.05 | 0.13 ± 0.01 | 0.36 ± 0.23 | –
Clinical Chemistry
Urea nitrogen (mg/dL)
Day 3 | 8.5 ± 0.3 | 10.2 ± 0.7 | 9.9 ± 0.8 | 14.4 ± 0.9** | 22.3 ± 1.5** | 25.3 ± 0.7**
Day 23 | 9.3 ± 0.4 | 8.4 ± 0.4 | 8.5 ± 0.5 | 10.8 ± 0.5* | 14.2 ± 1.6** | –
Week 14 | 15.4 ± 0.5 | 15.2 ± 0.4 | 14.5 ± 0.6 | 15.1 ± 0.4 | 18.0 ± 0.6 | –
Creatinine (mg/dL)
Day 3 | 0.21 ± 0.02 | 0.21 ± 0.02 | 0.19 ± 0.01 | 0.21 ± 0.01 | 0.27 ± 0.02 | 0.22 ± 0.02
Day 23 | 0.36 ± 0.02 | 0.31 ± 0.01 | 0.34 ± 0.02 | 0.33 ± 0.02 | 0.36 ± 0.04 | –
Week 14 | 0.36 ± 0.02 | 0.35 ± 0.02 | 0.34 ± 0.02 | 0.34 ± 0.02 | 0.33 ± 0.03 | –
Glucose (mg/dL)
Day 3 | 142 ± 4 | 133 ± 3 | 137 ± 4 | 157 ± 4* | 170 ± 19* | 176 ± 7**
Day 23 | 125 ± 4 | 136 ± 5 | 123 ± 7 | 146 ± 6** | 144 ± 12* | –
Week 14 | 121 ± 2 | 129 ± 4 | 130 ± 6 | 128 ± 2* | 153 ± 11** | –
Total protein (g/dL)
Day 3 | 5.5 ± 0.0 | 5.6 ± 0.0 | 5.6 ± 0.1 | 6.1 ± 0.1** | 6.3 ± 0.1** | 6.0 ± 0.1**
Day 23 | 6.3 ± 0.1 | 6.2 ± 0.1 | 6.3 ± 0.1 | 6.4 ± 0.1 | 6.7 ± 0.1* | –
Week 14 | 7.1 ± 0.1 | 7.1 ± 0.1 | 7.2 ± 0.1 | 7.0 ± 0.1 | 7.0 ± 0.2 | –
Albumin (g/dL)
Day 3 | 4.2 ± 0.0 | 4.2 ± 0.0 | 4.2 ± 0.0 | 4.6 ± 0.1** | 4.7 ± 0.1** | 4.5 ± 0.1**
Day 23 | 4.5 ± 0.0 | 4.4 ± 0.0 | 4.5 ± 0.1 | 4.6 ± 0.1 | 4.7 ± 0.1 | –
Week 14 | 4.7 ± 0.0 | 4.8 ± 0.1 | 4.8 ± 0.0 | 4.7 ± 0.1 | 4.6 ± 0.1 | –
Globulin (g/dL)
Day 3 | 1.3 ± 0.0 | 1.3 ± 0.0 | 1.3 ± 0.0 | 1.5 ± 0.0** | 1.6 ± 0.1** | 1.5 ± 0.1**
Day 23 | 1.8 ± 0.0 | 1.7 ± 0.0 | 1.9 ± 0.1 | 1.8 ± 0.1 | 2.0 ± 0.1 | –
Week 14 | 2.4 ± 0.0 | 2.4 ± 0.0 | 2.4 ± 0.1 | 2.2 ± 0.1 | 2.4 ± 0.1 | –
Albumin/globulin ratio
Day 3 | 3.2 ± 0.1 | 3.2 ± 0.1 | 3.2 ± 0.0 | 3.0 ± 0.1 | 3.0 ± 0.1 | 3.1 ± 0.1
Day 23 | 2.5 ± 0.1 | 2.6 ± 0.1 | 2.4 ± 0.1 | 2.6 ± 0.1 | 2.3 ± 0.1 | –
Week 14 | 1.9 ± 0.0 | 2.0 ± 0.0 | 2.0 ± 0.1 | 2.1 ± 0.1* | 1.9 ± 0.1 | –
Cholesterol (mg/dL)
Day 3 | 123 ± 3 | 117 ± 3 | 116 ± 3 | 119 ± 3 | 118 ± 4 | 107 ± 4*
Day 23 | 100 ± 4 | 93 ± 2 | 99 ± 3 | 104 ± 5 | 116 ± 5 | –
Week 14 | 114 ± 4 | 105 ± 3 | 107 ± 4 | 98 ± 4** | 86 ± 3** | –
Triglycerides (mg/dL)
Day 3 | 32 ± 2 | 28 ± 2 | 20 ± 1** | 18 ± 1** | 21 ± 3** | 24 ± 2**
Day 23 | 29 ± 2 | 26 ± 3 | 25 ± 2 | 28 ± 3 | 39 ± 9 | –
Week 14 | 52 ± 4 | 50 ± 5 | 48 ± 4 | 66 ± 5 | 78 ± 16 | –
Alanine aminotransferase (IU/L)
Day 3 | 72 ± 3 | 60 ± 3* | 57 ± 2** | 50 ± 2** | 41 ± 2** | 48 ± 4**
Day 23 | 44 ± 1 | 48 ± 2 | 51 ± 2** | 49 ± 2* | 64 ± 10** | –
Week 14 | 55 ± 2 | 69 ± 6** | 69 ± 3** | 73 ± 2** | 92 ± 12** | –
Alkaline phosphatase (IU/L)
Day 3 | 312 ± 9 | 274 ± 11* | 265 ± 6** | 246 ± 10** | 186 ± 4** | 172 ± 9**
Day 23 | 197 ± 7 | 205 ± 9 | 214 ± 9 | 233 ± 9* | 206 ± 14 | –
Week 14 | 156 ± 5 | 175 ± 6* | 204 ± 7** | 216 ± 6** | 238 ± 24** | –
Creatine kinase (IU/L)
Day 3 | 627 ± 111 | 526 ± 43 | 518 ± 45 | 573 ± 91 | 315 ± 26** | 416 ± 39*
Day 23 | 271 ± 20 | 352 ± 39 | 351 ± 34 | 429 ± 62** | 485 ± 63** | –
Week 14 | 196 ± 29 | 193 ± 21 | 223 ± 30 | 242 ± 26 | 1,014 ± 694** | –
Sorbitol dehydrogenase (IU/L)
Day 3 | 11 ± 1 | 11 ± 1 | 11 ± 1 | 11 ± 2 | 15 ± 1* | 15 ± 1*
Day 23 | 12 ± 0 | 12 ± 1 | 12 ± 1 | 11 ± 1 | 14 ± 1 | –
Week 14 | 14 ± 1 | 12 ± 1 | 12 ± 1 | 12 ± 1 | 12 ± 0 | –
Bile acids (µmol/L)
Day 3 | 32.1 ± 4.4 | 27.4 ± 4.4 | 20.6 ± 4.2* | 17.3 ± 3.4* | 10.1 ± 1.6** | 10.9 ± 1.1**
Day 23 | 12.2 ± 2.1 | 14.9 ± 2.3 | 23.4 ± 5.1 | 14.2 ± 2.8 | 35.3 ± 16.8 | –
Week 14 | 10.6 ± 2.3 | 29.3 ± 7.1* | 26.7 ± 3.7* | 26.0 ± 2.3** | 24.8 ± 13.8 | –
Female
n
Day 3 | 10 | 10 | 10 | 10 | 10 | 9
Day 23 | 10 | 10 | 9 | 10 | 7 | 0
Week 14 | 10 | 10 | 10 | 10 | 8 | 0
Hematology
Hematocrit (spun) (%)
Day 3 | 43.9 ± 0.4 | 44.2 ± 0.3 | 43.3 ± 0.8 | 45.3 ± 0.5 | 48.5 ± 0.7** | 51.6 ± 0.7**
Day 23 | 46.8 ± 0.5 | 47.2 ± 0.4 | 48.1 ± 0.6 | 49.1 ± 0.5** | 52.3 ± 1.3** | –
Week 14 | 46.2 ± 0.5 | 47.4 ± 0.6 | 47.6 ± 0.5 | 49.1 ± 0.6** | 49.8 ± 1.0** | –
Packed cell volume (%)
Day 3 | 41.7 ± 0.5 | 41.9 ± 0.4 | 40.9 ± 0.7 | 43.4 ± 0.4* | 46.6 ± 0.7** | 50.3 ± 0.6**
Day 23 | 45.2 ± 0.4 | 45.8 ± 0.4 | 46.9 ± 0.6* | 47.6 ± 0.5** | 51.3 ± 1.3** | –
Week 14 | 45.0 ± 0.4 | 45.6 ± 0.6 | 46.1 ± 0.5 | 47.7 ± 0.7** | 48.6 ± 1.0** | –
Hemoglobin (g/dL)
Day 3 | 13.5 ± 0.2 | 13.7 ± 0.1 | 13.4 ± 0.2 | 14.1 ± 0.1** | 15.3 ± 0.2** | 16.6 ± 0.2**
Day 23 | 14.9 ± 0.1 | 15.1 ± 0.1 | 15.4 ± 0.2* | 15.7 ± 0.2** | 16.9 ± 0.4** | –
Week 14 | 15.2 ± 0.1 | 15.4 ± 0.2 | 15.6 ± 0.1 | 16.0 ± 0.2** | 16.4 ± 0.3** | –
Erythrocytes (10^6^/μL)
Day 3 | 6.34 ± 0.11 | 6.42 ± 0.05 | 6.42 ± 0.07 | 6.71 ± 0.10** | 7.38 ± 0.13** | 8.11 ± 0.10**
Day 23 | 7.31 ± 0.11 | 7.47 ± 0.09 | 7.79 ± 0.09** | 7.80 ± 0.09** | 8.53 ± 0.23** | –
Week 14 | 7.79 ± 0.10 | 8.17 ± 0.12* | 8.11 ± 0.10* | 8.37 ± 0.15** | 8.39 ± 0.16** | –
Reticulocytes (10^3^/μL)
Day 3 | 423 ± 13 | 439 ± 25 | 431 ± 14 | 465 ± 17 | 460 ± 18 | 511 ± 28*
Day 23 | 182 ± 8 | 225 ± 10 | 196 ± 5 | 223 ± 12* | 263 ± 30** | –
Week 14 | 192 ± 8 | 200 ± 4 | 206 ± 7 | 219 ± 9 | 216 ± 13 | –
Nucleated erythrocytes/100 leukocytes
Day 3 | 0.0 ± 0.0 | 0.2 ± 0.1 | 0.0 ± 0.0 | 0.0 ± 0.0 | 0.0 ± 0.0 | 0.2 ± 0.1
Day 23 | 0.0 ± 0.0 | 0.0 ± 0.0 | 0.0 ± 0.0 | 0.0 ± 0.0 | 0.1 ± 0.1 | –
Week 14 | 0.0 ± 0.0 | 0.0 ± 0.0 | 0.0 ± 0.0 | 0.0 ± 0.0 | 0.00 ± 0.0 | –
Mean cell volume (fL)
Day 3 | 65.7 ± 0.7 | 65.3 ± 0.5 | 63.6 ± 0.6 | 64.7 ± 0.5 | 63.2 ± 0.5** | 62.0 ± 0.5**
Day 23 | 61.8 ± 0.5 | 61.3 ± 0.4 | 60.2 ± 0.5 | 61.1 ± 0.3 | 60.2 ± 0.6 | –
Week 14 | 57.8 ± 0.4 | 55.8 ± 0.5* | 56.9 ± 0.4 | 57.0 ± 0.5 | 57.9 ± 0.6 | –
Mean cell hemoglobin (pg)
Day 3 | 21.3 ± 0.2 | 21.3 ± 0.2 | 20.9 ± 0.2 | 21.1 ± 0.2 | 20.8 ± 0.2* | 20.5 ± 0.2**
Day 23 | 20.3 ± 0.2 | 20.2 ± 0.1 | 19.8 ± 0.2 | 20.1 ± 0.1 | 19.8 ± 0.2 | –
Week 14 | 19.5 ± 0.2 | 18.9 ± 0.2* | 19.3 ± 0.1 | 19.1 ± 0.1 | 19.5 ± 0.2 | –
Mean cell hemoglobin concentration (pg)
Day 3 | 32.4 ± 0.2 | 32.7 ± 0.1 | 32.8 ± 0.1 | 32.6 ± 0.2 | 32.9 ± 0.1 | 33.1 ± 0.1**
Day 23 | 32.9 ± 0.1 | 33.0 ± 0.1 | 32.9 ± 0.1 | 32.9 ± 0.1 | 32.9 ± 0.1 | –
Week 14 | 33.8 ± 0.1 | 33.8 ± 0.1 | 33.9 ± 0.1 | 33.6 ± 0.2 | 33.7 ± 0.1 | –
Platelets (10^3^/μL)
Day 3 | 1,309 ± 38 | 1,182 ± 57 | 1,309 ± 49 | 1,305 ± 50 | 1,435 ± 39 | 1,550 ± 85*
Day 23 | 1,006 ± 34 | 934 ± 28 | 1,043 ± 45 | 996 ± 38 | 859 ± 30* | –
Week 14 | 919 ± 25 | 943 ± 15 | 807 ± 43* | 829 ± 27* | 801 ± 38* | –
Leukocytes (10^3^/μL)
Day 3 | 12.51 ± 0.49 | 12.62 ± 0.51 | 11.32 ± 0.47 | 12.62 ± 0.92 | 11.06 ± 0.97 | 7.95 ± 0.84**
Day 23 | 9.21 ± 0.65 | 7.93 ± 0.60 | 10.23 ± 0.56 | 10.42 ± 0.72 | 8.16 ± 0.79 | –
Week 14 | 10.48 ± 0.51 | 11.59 ± 0.78 | 10.88 ± 0.56 | 11.15 ± 1.00 | 8.29 ± 0.84 | –
Segmented neutrophils (10^3^/μL)
Day 3 | 1.15 ± 0.10 | 1.02 ± 0.10 | 0.98 ± 0.10 | 1.21 ± 0.12 | 1.44 ± 0.14 | 2.71 ± 0.23**
Day 23 | 1.19 ± 0.17 | 0.81 ± 0.06 | 1.61 ± 0.13 | 2.28 ± 0.29** | 3.05 ± 0.75** | –
Week 14 | 1.38 ± 0.15 | 1.85 ± 0.11** | 2.03 ± 0.19** | 3.52 ± 0.43** | 3.07 ± 0.57** | –
Bands (10^3^/μL)
Day 3 | 0.00 ± 0.00 | 0.00 ± 0.00 | 0.00 ± 0.00 | 0.00 ± 0.00 | 0.00 ± 0.00 | 0.00 ± 0.00
Day 23 | 0.00 ± 0.00 | 0.00 ± 0.00 | 0.00 ± 0.00 | 0.00 ± 0.00 | 0.00 ± 0.00 | –
Week 14 | 0.00 ± 0.00 | 0.00 ± 0.00 | 0.00 ± 0.00 | 0.00 ± 0.00 | 0.00 ± 0.00 | –
Lymphocytes (10^3^/μL)
Day 3 | 11.01 ± 0.51 | 11.27 ± 0.46 | 10.01 ± 0.46 | 11.10 ± 0.85 | 9.38 ± 0.89 | 5.11 ± 0.72**
Day 23 | 7.76 ± 0.64 | 6.92 ± 0.56 | 8.34 ± 0.48 | 7.82 ± 0.68 | 4.92 ± 0.28** | –
Week 14 | 8.82 ± 0.42 | 9.41 ± 0.69 | 8.57 ± 0.62 | 7.35 ± 0.69 | 4.88 ± 0.69** | –
Monocytes (10^3^/μL)
Day 3 | 0.18 ± 0.03 | 0.15 ± 0.03 | 0.17 ± 0.03 | 0.14 ± 0.03 | 0.12 ± 0.06* | 0.09 ± 0.04*
Day 23 | 0.13 ± 0.02 | 0.09 ± 0.01 | 0.11 ± 0.02 | 0.16 ± 0.07 | 0.04 ± 0.01** | –
Week 14 | 0.07 ± 0.02 | 0.09 ± 0.02 | 0.07 ± 0.01 | 0.09 ± 0.05 | 0.06 ± 0.01 | –
Basophils (10^3^/μL)
Day 3 | 0.022 ± 0.004 | 0.021 ± 0.002 | 0.032 ± 0.007 | 0.036 ± 0.006 | 0.031 ± 0.010 | 0.002 ± 0.001**
Day 23 | 0.012 ± 0.001 | 0.015 ± 0.006 | 0.031 ± 0.010 | 0.027 ± 0.014 | 0.010 ± 0.004 | –
Week 14 | 0.015 ± 0.003 | 0.025 ± 0.007 | 0.015 ± 0.003 | 0.010 ± 0.003 | 0.009 ± 0.004 | –
Eosinophils (10^3^/μL)
Day 3 | 0.14 ± 0.01 | 0.16 ± 0.02 | 0.13 ± 0.01 | 0.14 ± 0.02 | 0.10 ± 0.01 | 0.04 ± 0.02**
Day 23 | 0.12 ± 0.01 | 0.10 ± 0.01 | 0.14 ± 0.02 | 0.14 ± 0.01 | 0.14 ± 0.02 | –
Week 14 | 0.19 ± 0.01 | 0.21 ± 0.02 | 0.20 ± 0.04 | 0.17 ± 0.03 | 0.26 ± 0.04 | –
Clinical Chemistry
Urea nitrogen (mg/dL)
Day 3 | 10.4 ± 0.7 | 8.9 ± 0.7 | 11.2 ± 1.1 | 12.6 ± 1.1 | 18.1 ± 0.9** | 24.4 ± 0.8**
Day 23 | 10.0 ± 0.3 | 10.5 ± 0.6 | 10.3 ± 0.5 | 14.1 ± 0.8** | 17.3 ± 1.1** | –
Week 14 | 15.3 ± 0.7 | 15.5 ± 0.3 | 13.1 ± 0.5 | 16.9 ± 1.0 | 18.8 ± 1.5 | –
Creatinine (mg/dL)
Day 3 | 0.34 ± 0.02 | 0.34 ± 0.02 | 0.34 ± 0.02 | 0.33 ± 0.02 | 0.34 ± 0.02 | 0.36 ± 0.02
Day 23 | 0.38 ± 0.01 | 0.37 ± 0.02 | 0.37 ± 0.02 | 0.41 ± 0.02 | 0.41 ± 0.03 | –
Week 14 | 0.39 ± 0.01 | 0.41 ± 0.02 | 0.35 ± 0.02 | 0.39 ± 0.02 | 0.36 ± 0.02 | –
Glucose (mg/dL)
Day 3 | 137 ± 2 | 138 ± 4 | 145 ± 3 | 149 ± 3* | 156 ± 4** | 163 ± 9**
Day 23 | 130 ± 5 | 131 ± 5 | 141 ± 3 | 143 ± 5 | 152 ± 9* | –
Week 14 | 129 ± 4 | 117 ± 1 | 127 ± 5 | 134 ± 4 | 145 ± 13 | –
Total protein (g/dL)
Day 3 | 5.8 ± 0.1 | 5.7 ± 0.1 | 6.0 ± 0.1 | 6.0 ± 0.0* | 6.2 ± 0.1** | 6.1 ± 0.1**
Day 23 | 6.4 ± 0.1 | 6.3 ± 0.0 | 6.5 ± 0.1 | 6.5 ± 0.1 | 6.6 ± 0.1 | –
Week 14 | 7.1 ± 0.1 | 7.2 ± 0.1 | 6.8 ± 0.1 | 7.1 ± 0.1 | 7.0 ± 0.1 | –
Albumin (g/dL)
Day 3 | 4.6 ± 0.1 | 4.5 ± 0.1 | 4.7 ± 0.0 | 4.6 ± 0.0 | 4.7 ± 0.1 | 4.6 ± 0.1
Day 23 | 4.7 ± 0.1 | 4.7 ± 0.1 | 4.7 ± 0.1 | 4.7 ± 0.1 | 4.8 ± 0.1 | –
Week 14 | 5.1 ± 0.1 | 5.1 ± 0.1 | 4.8 ± 0.1** | 4.8 ± 0.1** | 4.7 ± 0.1** | –
Globulin (g/dL)
Day 3 | 1.2 ± 0.0 | 1.2 ± 0.0 | 1.3 ± 0.0 | 1.4 ± 0.0** | 1.5 ± 0.1** | 1.5 ± 0.1**
Day 23 | 1.7 ± 0.1 | 1.6 ± 0.0 | 1.7 ± 0.1 | 1.8 ± 0.0 | 1.8 ± 0.1 | –
Week 14 | 2.0 ± 0.1 | 2.1 ± 0.1 | 2.0 ± 0.1 | 2.3 ± 0.1** | 2.3 ± 0.1** | –
Albumin/globulin ratio
Day 3 | 3.7 ± 0.1 | 3.7 ± 0.1 | 3.6 ± 0.1 | 3.4 ± 0.1* | 3.2 ± 0.1** | 3.1 ± 0.1**
Day 23 | 2.9 ± 0.2 | 3.1 ± 0.1 | 2.7 ± 0.1 | 2.6 ± 0.1** | 2.6 ± 0.1* | –
Week 14 | 2.6 ± 0.1 | 2.4 ± 0.1* | 2.4 ± 0.1* | 2.1 ± 0.1** | 2.0 ± 0.1** | –
Cholesterol (mg/dL)
Day 3 | 114 ± 5 | 114 ± 4 | 111 ± 4 | 111 ± 5 | 109 ± 4 | 81 ± 5**
Day 23 | 102 ± 5 | 104 ± 5 | 109 ± 4 | 105 ± 6 | 87 ± 6 | –
Week 14 | 98 ± 5 | 110 ± 5 | 102 ± 3 | 99 ± 5 | 80 ± 4 | –
Triglycerides (mg/dL)
Day 3 | 36 ± 2 | 33 ± 1 | 32 ± 3 | 29 ± 3 | 29 ± 2 | 31 ± 1
Day 23 | 32 ± 1 | 35 ± 3 | 40 ± 3 | 34 ± 3 | 34 ± 4 | –
Week 14 | 37 ± 3 | 43 ± 2 | 43 ± 2 | 73 ± 9** | 59 ± 8** | –
Alanine aminotransferase (IU/L)
Day 3 | 57 ± 2 | 49 ± 3 | 44 ± 2** | 44 ± 2** | 35 ± 2** | 39 ± 3**
Day 23 | 42 ± 4 | 36 ± 1 | 40 ± 3 | 45 ± 2 | 49 ± 4 | –
Week 14 | 53 ± 3 | 54 ± 2 | 64 ± 6 | 66 ± 4 | 88 ± 6** | –
Alkaline phosphatase (IU/L)
Day 3 | 245 ± 9 | 222 ± 7 | 218 ± 9* | 197 ± 6** | 158 ± 7** | 134 ± 6**
Day 23 | 124 ± 5 | 121 ± 5 | 148 ± 8* | 156 ± 8** | 152 ± 4** | –
Week 14 | 127 ± 6 | 146 ± 6* | 176 ± 23* | 184 ± 9** | 220 ± 17** | –
Creatine kinase (IU/L)
Day 3 | 540 ± 74 | 586 ± 113 | 651 ± 143 | 428 ± 81 | 476 ± 69 | 417 ± 50
Day 23 | 370 ± 123 | 269 ± 35 | 373 ± 51 | 316 ± 44 | 465 ± 52** | –
Week 14 | 188 ± 20 | 200 ± 26 | 212 ± 20 | 258 ± 43 | 449 ± 123* | –
Sorbitol dehydrogenase (IU/L)
Day 3 | 10 ± 1 | 10 ± 1 | 11 ± 1 | 10 ± 1 | 10 ± 1 | 14 ± 1*
Day 23 | 14 ± 3 | 11 ± 0 | 11 ± 1 | 12 ± 1 | 12 ± 1 | –
Week 14 | 12 ± 0 | 11 ± 1 | 12 ± 1 | 11 ± 1 | 11 ± 1 | –
Bile acids (µmol/L)
Day 3 | 19.4 ± 4.5 | 20.3 ± 5.6 | 13.9 ± 4.1 | 9.1 ± 1.5 | 7.8 ± 0.8* | 10.2 ± 1.4
Day 23 | 9.6 ± 1.6 | 11.9 ± 1.3 | 9.4 ± 2.5 | 13.8 ± 4.2 | 12.7 ± 2.6 | –
Week 14 | 12.5 ± 4.8 | 18.4 ± 4.0 | 43.4 ± 13.9** | 25.5 ± 3.4** | 24.2 ± 3.8** | –

* Significantly different (P ≤ 0.05) from the chamber control group by Dunn’s or Shirley’s test.

** P ≤ 0.01.

^a^ Data are presented as mean ± standard error. Statistical tests were performed on unrounded data. Due to 100% mortality in clinical pathology and core study rats exposed to 7.0 ppm, no data are available for these groups at day 23 or week 14.

Table B-2 Hematology Data for Mice in the Three-month Inhalation Study of o-Phthalaldehyde^a^

| Chamber Control | 0.44 ppm | 0.88 ppm | 1.75 ppm | 3.5 ppm
Male
n | 10 | 10 | 10 | 10 | 5
Hematology
Hematocrit (spun) (%) | 50.2 ± 0.4 | 50.3 ± 0.3 | 50.3 ± 0.4 | 49.0 ± 0.3* | 47.5 ± 0.9*
Packed cell volume (%) | 49.8 ± 0.4 | 50.3 ± 0.5 | 49.7 ± 0.3 | 47.9 ± 0.3** | 46.4 ± 1.0**
Hemoglobin (g/dL) | 16.0 ± 0.1 | 16.4 ± 0.1 | 16.1 ± 0.1 | 15.6 ± 0.1* | 15.0 ± 0.3*
Erythrocytes (10^6^/μL) | 10.38 ± 0.07 | 10.66 ± 0.12 | 10.52 ± 0.08 | 10.04 ± 0.09* | 9.72 ± 0.14**
Reticulocytes (10^3^/μL) | 256 ± 9 | 257 ± 14 | 258 ± 9 | 224 ± 10 | 228 ± 28
Nucleated erythrocytes/100 leukocytes | 0.00 ± 0.00 | 0.00 ± 0.00 | 0.00 ± 0.00 | 0.00 ± 0.00 | 0.00 ± 0.00
Howell-Jolly bodies (% erythrocytes) | 0.2 ± 0.0 | 0.2 ± 0.0 | 0.2 ± 0.0 | 0.2 ± 0.0 | 0.2 ± 0.0
Mean cell volume (fL) | 47.9 ± 0.2 | 47.2 ± 0.1 | 47.2 ± 0.2* | 47.8 ± 0.2 | 47.7 ± 0.5
Mean cell hemoglobin (pg) | 15.5 ± 0.1 | 15.4 ± 0.1 | 15.3 ± 0.1 | 15.5 ± 0.1 | 15.4 ± 0.1
Mean cell hemoglobin concentration (g/dL) | 32.2 ± 0.1 | 32.6 ± 0.1 | 32.5 ± 0.2 | 32.5 ± 0.1 | 32.3 ± 0.1
Platelets (10^3^/μL) | 992 ± 11 | 911 ± 34* | 931 ± 16 | 978 ± 18 | 1,090 ± 112
Leukocytes (10^3^/μL) | 2.32 ± 0.19 | 3.32 ± 0.21** | 3.08 ± 0.12** | 4.61 ± 0.42** | 6.15 ± 1.22**
Segmented neutrophils (10^3^/μL) | 0.30 ± 0.04 | 0.42 ± 0.02 | 0.41 ± 0.03 | 0.87 ± 0.08** | 2.90 ± 1.14**
Bands (10^3^/μL) | 0.00 ± 0.00 | 0.00 ± 0.00 | 0.00 ± 0.00 | 0.00 ± 0.00 | 0.00 ± 0.00
Lymphocytes (10^3^/μL) | 1.91 ± 0.15 | 2.82 ± 0.19** | 2.57 ± 0.13** | 3.57 ± 0.35** | 2.83 ± 0.21**
Monocytes (10^3^/μL) | 0.06 ± 0.02 | 0.05 ± 0.01 | 0.04 ± 0.01 | 0.04 ± 0.02 | 0.22 ± 0.10
Basophils (10^3^/μL) | 0.018 ± 0.002 | 0.018 ± 0.002 | 0.020 ± 0.004 | 0.017 ± 0.004 | 0.008 ± 0.002
Eosinophils (10^3^/μL) | 0.02 ± 0.00 | 0.02 ± 0.01 | 0.05 ± 0.01 | 0.12 ± 0.02** | 0.19 ± 0.06**
Female
n | 10 | 10 | 10 | 10 | 6
Hematology
Hematocrit (spun) (%) | 50.7 ± 0.6 | 50.2 ± 0.3 | 48.8 ± 0.4** | 49.3 ± 0.7* | 46.0 ± 1.0**^b^
Packed cell volume (%) | 50.1 ± 0.6 | 50.2 ± 0.3 | 48.6 ± 0.4** | 48.7 ± 0.6* | 47.1 ± 0.4**
Hemoglobin (g/dL) | 16.5 ± 0.2 | 16.3 ± 0.1 | 15.8 ± 0.1** | 15.9 ± 0.2** | 15.2 ± 0.2**
Erythrocytes (10^6^/μL) | 10.33 ± 0.08 | 10.44 ± 0.05 | 10.10 ± 0.07 | 10.16 ± 0.11 | 9.70 ± 0.11**
Reticulocytes (10^3^/μL) | 285 ± 23 | 279 ± 16 | 299 ± 16 | 276 ± 13 | 243 ± 13
Nucleated erythrocytes/100 leukocytes | 0.00 ± 0.00 | 0.00 ± 0.00 | 0.00 ± 0.00 | 0.00 ± 0.00 | 0.00 ± 0.00
Howell-Jolly bodies (% erythrocytes) | 0.1 ± 0.0 | 0.1 ± 0.0 | 0.1 ± 0.0 | 0.1 ± 0.0 | 0.1 ± 0.0
Mean cell volume (fL) | 48.4 ± 0.3 | 48.1 ± 0.2 | 48.1 ± 0.1 | 48.0 ± 0.2 | 48.5 ± 0.3
Mean cell hemoglobin (pg) | 15.9 ± 0.1 | 15.7 ± 0.1* | 15.7 ± 0.0* | 15.7 ± 0.1** | 15.6 ± 0.1*
Mean cell hemoglobin concentration (g/dL) | 32.9 ± 0.1 | 32.5 ± 0.1 | 32.6 ± 0.1 | 32.7 ± 0.1 | 32.2 ± 0.2*
Platelets (10^3^/μL) | 846 ± 55 | 835 ± 18 | 895 ± 20 | 890 ± 14 | 883 ± 100
Leukocytes (10^3^/μL) | 3.80 ± 0.51 | 2.78 ± 0.18 | 3.37 ± 0.34 | 4.01 ± 0.36 | 5.31 ± 0.36*
Segmented neutrophils (10^3^/μL) | 0.69 ± 0.23 | 0.47 ± 0.08 | 0.61 ± 0.06 | 0.84 ± 0.12 | 2.14 ± 0.31**
Bands (10^3^/μL) | 0.00 ± 0.00 | 0.00 ± 0.00 | 0.00 ± 0.00 | 0.00 ± 0.00 | 0.00 ± 0.00
Lymphocytes (10^3^/μL) | 3.03 ± 0.32 | 2.27 ± 0.14 | 2.65 ± 0.30 | 3.04 ± 0.24 | 2.94 ± 0.37
Monocytes (10^3^/μL) | 0.03 ± 0.01 | 0.02 ± 0.00 | 0.06 ± 0.02 | 0.04 ± 0.02 | 0.04 ± 0.01
Basophils (10^3^/μL) | 0.015 ± 0.004 | 0.014 ± 0.006 | 0.019 ± 0.003 | 0.021 ± 0.003 | 0.002 ± 0.002
Eosinophils (10^3^/μL) | 0.03 ± 0.01 | 0.02 ± 0.01 | 0.03 ± 0.01 | 0.07 ± 0.01* | 0.19 ± 0.05**

* Significantly different (P ≤ 0.05) from the chamber control group by Dunn’s or Shirley’s test.

** P ≤ 0.01.

^a^ Data are presented as mean ± standard error. Statistical tests were performed on unrounded data. Due to 100% mortality in mice exposed to 7.0 ppm, no data are available for this group.

^b^ n = 5.