# Appendix A Summary of Nonneoplastic Lesions in Rats and Mice

Table A-1 Summary of the Incidence of Nonneoplastic Lesions in Male Rats in the Three-month Inhalation Study of o-Phthalaldehyde^a^

| Chamber Control | 0.44 ppm | 0.88 ppm | 1.75 ppm | 3.5 ppm | 7.0 ppm
Disposition Summary
Animals initially in study | 10 | 10 | 10 | 10 | 10 | 10
Early deaths
Moribund | – | – | – | – | 3 | 2
Natural deaths | – | – | – | – | 4 | 8
Survivors
Terminal euthanasia | 10 | 10 | 10 | 10 | 3 | –
Animals examined microscopically | 10 | 10 | 10 | 10 | 10 | 10
Alimentary System
Esophagus | (10) | (0) | (0) | (9) | (10) | (10)
Intestine large, cecum | (10) | (0) | (0) | (10) | (10) | (8)
Intestine large, colon | (10) | (0) | (0) | (10) | (10) | (8)
Intestine large, rectum | (10) | (0) | (0) | (10) | (10) | (10)
Intestine small, duodenum | (10) | (0) | (0) | (10) | (10) | (10)
Intestine small, ileum | (10) | (0) | (0) | (10) | (10) | (8)
Diverticulum | – | – | – | – | – | 1 (13%)
Intestine small, jejunum | (10) | (0) | (0) | (10) | (10) | (7)
Liver | (10) | (1) | (0) | (10) | (10) | (10)
Fibrosis | – | – | – | – | 1 (10%) | –
Hepatodiaphragmatic nodule | – | 1 (100%) | – | – | – | –
Hepatocyte, degeneration, focal | 1 (10%) | – | – | – | – | –
Pancreas | (10) | (0) | (0) | (10) | (10) | (10)
Salivary glands | (10) | (0) | (0) | (10) | (10) | (10)
Stomach, forestomach | (10) | (0) | (0) | (10) | (10) | (10)
Cyst, squamous | – | – | – | – | – | 1 (10%)
Hyperplasia, squamous | – | – | – | 1 (10%) | – | –
Stomach, glandular | (10) | (0) | (0) | (10) | (10) | (10)
Cardiovascular System
Blood vessel | (10) | (0) | (0) | (10) | (0) | (0)
Heart | (10) | (0) | (1) | (10) | (10) | (10)
Cardiomyopathy | 1 (10%) | – | – | 1 (10%) | – | –
Congestion | – | – | 1 (100%) | – | – | –
Endocrine System
Adrenal cortex | (10) | (0) | (0) | (10) | (10) | (10)
Adrenal medulla | (10) | (0) | (0) | (10) | (10) | (10)
Islets, pancreatic | (10) | (0) | (0) | (10) | (10) | (10)
Parathyroid gland | (10) | (0) | (0) | (8) | (10) | (9)
Pituitary gland | (10) | (0) | (0) | (10) | (10) | (10)
Thyroid gland | (10) | (0) | (0) | (10) | (10) | (10)
General Body System
None | – | – | – | – | – | –
Genital System
Epididymis | (10) | (10) | (10) | (10) | (10) | (10)
Hypospermia | – | – | 1 (10%) | – | 1 (10%) | –
Infiltration cellular, mononuclear cell | – | – | – | – | – | 1 (10%)
Duct, exfoliated germ cell | – | – | 1 (10%) | 1 (10%) | 5 (50%) | 4 (40%)
Epithelium, apoptosis | – | – | – | – | 3 (30%) | 5 (50%)
Penis | (0) | (0) | (0) | (0) | (1) | (0)
Inflammation, suppurative | – | – | – | – | 1 (100%) | –
Preputial gland | (10) | (0) | (0) | (9) | (10) | (10)
Inflammation, chronic active | 1 (10%) | – | – | – | 1 (10%) | –
Prostate | (10) | (0) | (0) | (10) | (10) | (10)
Inflammation, chronic active | – | – | – | 1 (10%) | – | –
Seminal vesicle | (10) | (0) | (0) | (10) | (10) | (10)
Atrophy | – | – | – | – | 1 (10%) | –
Testes | (10) | (10) | (10) | (10) | (10) | (10)
Exfoliated germ cell, focal | – | – | – | – | 1 (10%) | 2 (20%)
Immature | – | – | – | – | 4 (40%) | 10 (100%)
Elongated spermatid, degeneration | – | – | – | – | 4 (40%) | –
Germinal epithelium, apoptosis | – | – | – | – | 4 (40%) | 6 (60%)
Germinal epithelium, atrophy, multifocal | – | – | 1 (10%) | – | – | –
Germinal epithelium, degeneration, focal | 1 (10%) | – | – | – | – | –
Germinal epithelium, degeneration, multifocal | – | – | – | 1 (10%) | – | –
Interstitial cell, atrophy | – | – | – | – | 7 (70%) | 10 (100%)
Round spermatid, degeneration | – | – | – | – | – | 2 (20%)
Seminiferous tubule, vacuolation | – | – | – | – | 3 (30%) | –
Hematopoietic System
Bone marrow | (10) | (0) | (0) | (10) | (10) | (10)
Lymph node | (0) | (1) | (0) | (0) | (0) | (0)
Pigmentation | – | 1 (100%) | – | – | – | –
Lymph node, bronchial | (7) | (0) | (0) | (6) | (7) | (6)
Lymph node, mandibular | (9) | (0) | (0) | (10) | (10) | (10)
Lymph node, mediastinal | (8) | (0) | (0) | (4) | (9) | (7)
Lymph node, mesenteric | (10) | (0) | (0) | (10) | (10) | (10)
Spleen | (10) | (9) | (10) | (10) | (10) | (10)
Atrophy, lymphoid | – | – | – | – | 6 (60%) | 10 (100%)
Thymus | (10) | (10) | (10) | (10) | (10) | (10)
Atrophy, lymphoid | – | – | – | – | 8 (80%) | 7 (70%)
Integumentary System
Mammary gland | (6) | (0) | (0) | (7) | (6) | (2)
Skin | (10) | (10) | (10) | (10) | (10) | (10)
Hyperplasia, squamous | – | – | – | – | 1 (10%) | 1 (10%)
Inflammation, suppurative | – | – | – | – | 1 (10%) | –
Adnexa, degeneration | – | – | – | – | 4 (40%) | 10 (100%)
Epithelium, hair follicle, parakeratosis | – | 7 (70%) | 4 (40%) | 7 (70%) | 3 (30%) | 10 (100%)
Musculoskeletal System
Bone | (10) | (0) | (0) | (10) | (10) | (10)
Maxilla, inflammation, chronic active | – | – | – | – | – | 1 (10%)
Nervous System
Brain | (10) | (0) | (0) | (10) | (10) | (10)
Respiratory System
Larynx | (10) | (10) | (10) | (10) | (10) | (10)
Inflammation, chronic active | 1 (10%) | 2 (20%) | 8 (80%) | 10 (100%) | 10 (100%) | 10 (100%)
Metaplasia, squamous | – | 1 (10%) | 8 (80%) | 10 (100%) | 10 (100%) | 10 (100%)
Necrosis | – | – | 1 (10%) | 5 (50%) | 9 (90%) | 10 (100%)
Regeneration | – | – | 3 (30%) | 2 (20%) | 2 (20%) | 6 (60%)
Lung | (10) | (10) | (10) | (10) | (10) | (10)
Alveolus, infiltration cellular, histiocyte | – | 1 (10%) | – | 3 (30%) | 9 (90%) | 1 (10%)
Alveolus, inflammation, suppurative | – | – | – | – | 3 (30%) | 6 (60%)
Bronchus, fibrosis | – | – | – | 1 (10%) | 2 (20%) | 1 (10%)
Bronchus, hyperplasia | – | – | – | 2 (20%) | 5 (50%) | 1 (10%)
Bronchus, inflammation, chronic active | – | – | – | 3 (30%) | 9 (90%) | 8 (80%)
Bronchus, metaplasia, squamous | – | – | – | 7 (70%) | 6 (60%) | 1 (10%)
Bronchus, necrosis | – | – | – | – | 5 (50%) | 7 (70%)
Bronchus, regeneration | – | – | – | – | 3 (30%) | 1 (10%)
Bronchus, goblet cell, hyperplasia | – | – | – | – | 1 (10%) | –
Perivascular, inflammation, chronic active | – | – | – | – | 2 (20%) | –
Nose | (10) | (10) | (10) | (10) | (10) | (10)
Inflammation, suppurative | – | 10 (100%) | 10 (100%) | 10 (100%) | 10 (100%) | 10 (100%)
Glands, olfactory epithelium, hyperplasia | – | – | – | 1 (10%) | 2 (20%) | 3 (30%)
Goblet cell, respiratory epithelium, hyperplasia | – | 4 (40%) | 6 (60%) | 2 (20%) | – | 1 (10%)
Olfactory epithelium, accumulation, hyaline droplet | 9 (90%) | 10 (100%) | 9 (90%) | 1 (10%) | – | –
Olfactory epithelium, atrophy | 2 (20%) | 10 (100%) | 10 (100%) | 10 (100%) | 7 (70%) | 6 (60%)
Olfactory epithelium, metaplasia, respiratory | 1 (10%) | 1 (10%) | 6 (60%) | 6 (60%) | 2 (20%) | –
Olfactory epithelium, metaplasia, squamous | – | – | – | 1 (10%) | 1 (10%) | 1 (10%)
Olfactory epithelium, necrosis | – | – | – | 1 (10%) | 3 (30%) | –
Olfactory epithelium, regeneration | – | – | 1 (10%) | – | 4 (40%) | –
Respiratory epithelium, accumulation, hyaline droplet | 1 (10%) | – | 1 (10%) | – | – | –
Respiratory epithelium, hyperplasia | 3 (30%) | 9 (90%) | 9 (90%) | 7 (70%) | 3 (30%) | –
Respiratory epithelium, metaplasia, squamous | – | 10 (100%) | 10 (100%) | 10 (100%) | 10 (100%) | 8 (80%)
Respiratory epithelium, necrosis | – | – | 3 (30%) | 5 (50%) | 10 (100%) | 10 (100%)
Respiratory epithelium, regeneration | – | – | 1 (10%) | – | 3 (30%) | 6 (60%)
Respiratory epithelium, ulcer | – | 1 (10%) | – | – | – | –
Turbinate, atrophy | – | – | 7 (70%) | 10 (100%) | – | –
Trachea | (10) | (10) | (10) | (10) | (10) | (10)
Fibrosis | – | – | – | 5 (50%) | 3 (30%) | –
Inflammation, chronic active | – | – | 4 (40%) | 8 (80%) | 9 (90%) | 10 (100%)
Metaplasia, squamous | – | – | 4 (40%) | 10 (100%) | 6 (60%) | 6 (60%)
Necrosis | – | – | – | 3 (30%) | 8 (80%) | 8 (80%)
Regeneration | – | – | – | 7 (70%) | 7 (70%) | 6 (60%)
Ulcer | – | – | – | – | 1 (10%) | 2 (20%)
Special Senses System
Eye | (10) | (10) | (10) | (10) | (10) | (10)
Anterior chamber, inflammation, suppurative | – | – | – | – | 4 (40%) | 5 (50%)
Cornea, hyperplasia | – | – | – | – | – | 2 (20%)
Cornea, inflammation, suppurative | 1 (10%) | 1 (10%) | 1 (10%) | 1 (10%) | 5 (50%) | 6 (60%)
Cornea, necrosis | – | – | 1 (10%) | – | 2 (20%) | 4 (40%)
Harderian gland | (10) | (0) | (0) | (10) | (10) | (10)
Urinary System
Kidney | (10) | (10) | (10) | (10) | (10) | (10)
Nephropathy | 10 (100%) | 10 (100%) | 9 (90%) | 7 (70%) | 1 (10%) | 2 (20%)
Urinary bladder | (10) | (0) | (0) | (10) | (10) | (10)

^a^ Number of animals examined microscopically at the site and the number of animals with lesion.

Table A-2 Summary of the Incidence of Nonneoplastic Lesions in Female Rats in the Three-month Inhalation Study of o-Phthalaldehyde^a^

| Chamber Control | 0.44 ppm | 0.88 ppm | | 1.75 ppm | 3.5 ppm | 7.0 ppm
Disposition Summary
Animals initially in study | 10 | 10 | 10 | | 10 | 10 | 10
Early deaths
Moribund | – | – | – | | – | 2 | 1
Natural deaths | – | – | – | | – | – | 9
Survivors
Terminal euthanasia | 10 | 10 | 10 | | 10 | 8
Animals examined microscopically | 10 | 10 | 10 | | 10 | 10 | 10
Alimentary System
Esophagus | (10) | (0) | (0) | | (0) | (10) | (10)
Intestine large, cecum | (10) | (0) | (0) | | (0) | (10) | (10)
Intestine large, colon | (10) | (0) | (0) | | (0) | (10) | (10)
Intestine large, rectum | (10) | (0) | (0) | | (0) | (10) | (10)
Intestine small, duodenum | (10) | (0) | (0) | | (0) | (10) | (10)
Intestine small, ileum | (10) | (0) | (0) | | (0) | (10) | (10)
Intestine small, jejunum | (10) | (0) | (0) | | (0) | (10) | (6)
Liver | (10) | (0) | (0) | | (0) | (10) | (10)
Mesentery | (0) | (0) | (1) | | (0) | (0) | (0)
Fat, degeneration | – | – | 1 (100%) | | – | – | –
Pancreas | (10) | (0) | (0) | | (0) | (10) | (10)
Salivary glands | (10) | (0) | (0) | | (0) | (10) | (10)
Stomach, forestomach | (10) | (0) | (0) | | (0) | (10) | (10)
Cyst, squamous | 1 (10%) | – | – | | – | – | –
Stomach, glandular | (10) | (9) | (9) | | (10) | (10) | (10)
Ulcer | – | – | – | | – | – | 2 (20%)
Cardiovascular System
Blood vessel | (10) | (0) | (0) | | (0) | (10) | (0)
Heart | (10) | (0) | (0) | | (0) | (10) | (10)
Cardiomyopathy | – | – | – | | – | – | 2 (20%)
Congestion | – | – | – | | – | – | 1 (10%)
Endocrine System
Adrenal cortex | (10) | (0) | (0) | | (0) | (10) | (10)
Adrenal medulla | (10) | (0) | (0) | | (0) | (10) | (10)
Islets, pancreatic | (10) | (0) | (0) | | (0) | (10) | (10)
Parathyroid gland | (8) | (0) | (0) | | (0) | (9) | (9)
Pituitary gland | (10) | (0) | (0) | | (0) | (10) | (10)
Thyroid gland | (10) | (0) | (0) | | (0) | (10) | (10)
General Body System
None | – | – | – | – | | – | –
Genital System
Clitoral gland | (10) | (0) | (0) | | (0) | (10) | (10)
Ovary | (10) | (0) | (0) | | (0) | (10) | (10)
Uterus | (10) | (0) | (0) | | (1) | (10) | (10)
Decidual reaction | – | – | – | | 1 (100%) | – | –
Hematopoietic System
Bone marrow | (10) | (0) | (0) | | (0) | (10) | (10)
Lymph node, bronchial | (8) | (0) | (0) | | (0) | (7) | (5)
Lymph node, mandibular | (9) | (0) | (0) | | (0) | (10) | (10)
Lymph node, mediastinal | (8) | (0) | (0) | | (0) | (6) | (10)
Lymph node, mesenteric | (10) | (0) | (0) | | (0) | (10) | (9)
Spleen | (10) | (10) | (10) | | (10) | (10) | (10)
Atrophy, lymphoid | – | – | – | | 1 (10%) | 4 (40%) | 10 (100%)
Thymus | (10) | (10) | (10) | | (10) | (9) | (10)
Atrophy, lymphoid | – | – | – | | – | 6 (67%) | 10 (100%)
Integumentary System
Mammary gland | (10) | (0) | (0) | | (0) | (10) | (10)
Skin | (10) | (10) | (10) | | (10) | (10) | (10)
Hyperplasia, squamous | – | – | – | | – | – | 1 (10%)
Adnexa, degeneration | – | 1 (10%) | – | | – | 1 (10%) | 10 (100%)
Epithelium, hair follicle, parakeratosis | – | 1 (10%) | 1 (10%) | | 3 (30%) | 3 (30%) | 6 (60%)
Hair follicle, atrophy | – | – | – | | – | 1 (10%) | –
Musculoskeletal System
Bone | (10) | (0) | (0) | | (0) | (10) | (10)
Nervous System
Brain | (10) | (0) | (0) | | (0) | (10) | (10)
Respiratory System
Larynx | (10) | (10) | (10) | | (10) | (10) | (10)
Inflammation, chronic active | – | 1 (10%) | 1 (10%) | | 9 (90%) | 10 (100%) | 10 (100%)
Metaplasia, squamous | – | 1 (10%) | 4 (40%) | | 10 (100%) | 10 (100%) | 10 (100%)
Necrosis | – | – | – | | 1 (10%) | 7 (70%) | 8 (80%)
Regeneration | – | – | 1 (10%) | | 3 (30%) | 1 (10%) | 2 (20%)
Ulcer | – | – | 1 (10%) | | 1 (10%) | – | –
Lung | (10) | (10) | (10) | | (10) | (10) | (10)
Alveolus, infiltration cellular, histiocyte | – | 2 (20%) | 1 (10%) | | 3 (30%) | 9 (90%) | 3 (30%)
Alveolus, inflammation, suppurative | – | – | – | | – | 2 (20%) | 4 (40%)
Bronchus, fibrosis | – | – | – | | 1 (10%) | 1 (10%) | 3 (30%)
Bronchus, hyperplasia | – | – | – | | 1 (10%) | 6 (60%) | 1 (10%)
Bronchus, inflammation, chronic active | – | – | – | | 2 (20%) | 10 (100%) | 10 (100%)
Bronchus, metaplasia, squamous | – | – | – | | 2 (20%) | 9 (90%) | –
Bronchus, necrosis | – | – | – | | – | 2 (20%) | 10 (100%)
Bronchus, regeneration | – | – | – | | – | 1 (10%) | 5 (50%)
Interstitium, fibrosis | – | – | 1 (10%) | | – | 2 (20%) | –
Interstitium, inflammation, granulomatous | – | – | – | | – | – | 2 (20%)
Perivascular, inflammation, chronic active | – | – | 1 (10%) | | 1 (10%) | 6 (60%) | –
Nose | (10) | (10) | (10) | | (10) | (10) | (10)
Foreign body | – | – | – | | – | – | 1 (10%)
Inflammation, suppurative | – | 9 (90%) | 10 (100%) | | 10 (100%) | 10 (100%) | 10 (100%)
Synechia | – | – | – | | 1 (10%) | – | –
Glands, olfactory epithelium, hyperplasia | – | 2 (20%) | – | | 2 (20%) | 2 (20%) | 2 (20%)
Goblet cell, respiratory epithelium, hyperplasia | – | – | – | | 1 (10%) | – | 1 (10%)
Olfactory epithelium, accumulation, hyaline droplet | 9 (90%) | 10 (100%) | 8 (80%) | | 4 (40%) | – | –
Olfactory epithelium, atrophy | – | 9 (90%) | 10 (100%) | | 10 (100%) | 10 (100%) | 7 (70%)
Olfactory epithelium, metaplasia, respiratory | – | 1 (10%) | 2 (20%) | | 5 (50%) | 7 (70%) | 1 (10%)
Olfactory epithelium, metaplasia, squamous | – | – | – | | 1 (10%) | – | –
Olfactory epithelium, necrosis | – | – | 1 (10%) | | – | 1 (10%) | –
Olfactory epithelium, regeneration | – | – | – | | – | 1 (10%) | –
Respiratory epithelium, accumulation, hyaline droplet | – | 4 (40%) | – | | – | – | –
Respiratory epithelium, hyperplasia | – | 9 (90%) | 7 (70%) | | 4 (40%) | 3 (30%) | 3 (30%)
Respiratory epithelium, metaplasia, squamous | – | 10 (100%) | 10 (100%) | | 10 (100%) | 10 (100%) | 10 (100%)
Respiratory epithelium, necrosis | – | 2 (20%) | 6 (60%) | | 9 (90%) | 10 (100%) | 10 (100%)
Respiratory epithelium, regeneration | – | – | 2 (20%) | | – | 1 (10%) | 3 (30%)
Respiratory epithelium, ulcer | – | – | – | | 1 (10%) | – | 1 (10%)
Turbinate, atrophy | – | 2 (20%) | 4 (40%) | | 10 (100%) | 10 (100%) | –
Trachea | (10) | (10) | (10) | | (10) | (10) | (10)
Fibrosis | – | – | – | | 2 (20%) | 6 (60%) | –
Inflammation, chronic active | – | – | 3 (30%) | | 5 (50%) | 10 (100%) | 10 (100%)
Metaplasia, squamous | – | – | 3 (30%) | | 10 (100%) | 7 (70%) | 7 (70%)
Necrosis | – | – | – | | 3 (30%) | 3 (30%) | 8 (80%)
Regeneration | – | – | 1 (10%) | | 7 (70%) | 10 (100%) | 9 (90%)
Ulcer | – | – | – | | – | 1 (10%) | 2 (20%)
Special Senses System
Eye | (10) | (10) | (10) | | (10) | (10) | (10)
Anterior chamber, inflammation, suppurative | – | – | – | | – | 1 (10%) | 5 (50%)
Cornea, hyperplasia | – | – | – | | – | – | 1 (10%)
Cornea, inflammation, suppurative | – | – | 1 (10%) | | – | 1 (10%) | 8 (80%)
Cornea, necrosis | – | – | – | | – | – | 7 (70%)
Harderian gland | (10) | (0) | (0) | | (0) | (10) | (10)
Urinary System
Kidney | (10) | (10) | (9) | | (10) | (10) | (10)
Nephropathy | 6 (60%) | 5 (50%) | 4 (44%) | | 5 (50%) | 1 (10%) | 2 (20%)
Urinary bladder | (10) | (0) | (0) | | (0) | (10) | (10)

^a^ Number of animals examined microscopically at the site and the number of animals with lesion.

Table A-3 Summary of the Incidence of Nonneoplastic Lesions in Male Mice in the Three-month Inhalation Study of o-Phthalaldehyde^a^

| Chamber Control | 0.44 ppm | 0.88 ppm | 1.75 ppm | 3.5 ppm | 7.0 ppm
Disposition Summary
Animals initially in study | 10 | 10 | 10 | 10 | 10 | 10
Early deaths
Moribund | – | – | – | – | 5 | 2
Natural deaths | – | – | – | – | – | 8
Survivors
Terminal euthanasia | 10 | 10 | 10 | 10 | 5 | –
Animals examined microscopically | 10 | 10 | 10 | 10 | 10 | 10
Alimentary System
Esophagus | (10) | (0) | (0) | (10) | (10) | (10)
Inflammation, chronic active | – | – | – | – | – | 1 (10%)
Necrosis | – | – | – | – | – | 1 (10%)
Gallbladder | (10) | (0) | (0) | (9) | (9) | (3)
Inflammation, neutrophil | 4 (40%) | – | – | – | – | –
Intestine large, cecum | (10) | (0) | (0) | (10) | (10) | (7)
Intestine large, colon | (10) | (0) | (0) | (10) | (10) | (8)
Intestine large, rectum | (10) | (0) | (0) | (10) | (10) | (7)
Intestine small, duodenum | (10) | (0) | (0) | (10) | (10) | (3)
Intestine small, ileum | (10) | (0) | (0) | (10) | (10) | (3)
Intestine small, jejunum | (10) | (0) | (0) | (10) | (10) | (3)
Liver | (10) | (0) | (0) | (10) | (10) | (10)
Necrosis | – | – | – | – | 2 (20%) | –
Pancreas | (10) | (0) | (0) | (10) | (10) | (10)
Salivary glands | (10) | (0) | (0) | (10) | (10) | (9)
Stomach, forestomach | (10) | (0) | (0) | (10) | (10) | (9)
Hyperplasia, squamous | – | – | – | – | 1 (10%) | –
Stomach, glandular | (10) | (0) | (0) | (10) | (10) | (8)
Cardiovascular System
Blood vessel | (10) | (0) | (0) | (10) | (0) | (2)
Heart | (10) | (0) | (0) | (10) | (10) | (10)
Endocrine System
Adrenal cortex | (10) | (0) | (0) | (10) | (10) | (10)
Adrenal medulla | (10) | (0) | (0) | (10) | (10) | (10)
Islets, pancreatic | (10) | (0) | (0) | (10) | (10) | (10)
Parathyroid gland | (7) | (0) | (0) | (7) | (6) | (4)
Pituitary gland | (10) | (0) | (0) | (9) | (10) | (9)
Thyroid gland | (10) | (0) | (0) | (10) | (9) | (10)
General Body System
None | – | – | – | – | – | –
Genital System
Epididymis | (10) | (10) | (10) | (10) | (10) | (10)
Duct, exfoliated germ cell | – | – | – | – | 4 (40%) | 1 (10%)
Preputial gland | (10) | (0) | (0) | (10) | (10) | (10)
Inflammation, chronic active | – | – | – | – | 1 (10%) | –
Prostate | (10) | (0) | (0) | (10) | (10) | (9)
Seminal vesicle | (10) | (0) | (0) | (10) | (10) | (10)
Inflammation, chronic | – | – | – | – | 1 (10%) | –
Testes | (10) | (10) | (10) | (10) | (10) | (10)
Germinal epithelium, depletion cellular, focal | – | 1 (10%) | – | – | – | –
Germinal epithelium, depletion cellular, multifocal | – | 1 (10%) | 1 (10%) | – | 7 (70%) | –
Interstitial cell, atrophy | – | – | – | – | 3 (30%) | –
Seminiferous tubule, dilation, focal | – | 2 (20%) | – | – | – | –
Hematopoietic System
Bone marrow | (10) | (0) | (0) | (10) | (10) | (10)
Hyperplasia | – | – | – | 2 (20%) | 5 (50%) | 7 (70%)
Lymph node, bronchial | (7) | (0) | (0) | (4) | (5) | (6)
Lymph node, mandibular | (4) | (0) | (0) | (6) | (9) | (5)
Lymph node, mediastinal | (4) | (0) | (0) | (1) | (4) | (3)
Lymph node, mesenteric | (10) | (0) | (0) | (10) | (10) | (7)
Spleen | (10) | (0) | (0) | (10) | (10) | (10)
Atrophy, lymphoid | – | – | – | – | – | 10 (100%)
Thymus | (10) | (10) | (10) | (10) | (9) | (10)
Atrophy, lymphoid | – | – | – | – | 5 (56%) | 10 (100%)
Integumentary System
Skin | (10) | (10) | (10) | (9) | (10) | (10)
Hyperplasia, squamous | – | 1 (10%) | – | – | 9 (90%) | 4 (40%)
Inflammation, chronic active | – | – | – | 1 (11%) | 10 (100%) | 9 (90%)
Ulcer | – | – | – | – | 1 (10%) | –
Adnexa, degeneration | – | 2 (20%) | – | 4 (44%) | 1 (10%) | 6 (60%)
Adnexa, pinna, degeneration | – | – | – | – | – | 10 (100%)
Epidermis, necrosis | – | – | – | – | – | 3 (30%)
Epithelium, hair follicle, parakeratosis | – | 3 (30%) | 4 (40%) | 2 (22%) | 2 (20%) | 10 (100%)
Epithelium, hair follicle, pinna, parakeratosis | – | – | – | – | – | 10 (100%)
Pinna, hyperplasia, squamous | – | – | – | – | – | 10 (100%)
Pinna, inflammation, chronic active | – | – | – | – | – | 10 (100%)
Musculoskeletal System
Bone | (10) | (0) | (0) | (10) | (10) | (10)
Nervous System
Brain | (10) | (0) | (0) | (10) | (10) | (10)
Respiratory System
Larynx | (10) | (10) | (9) | (10) | (10) | (10)
Inflammation, chronic active | – | – | – | 4 (40%) | 10 (100%) | 10 (100%)
Metaplasia, squamous | – | – | 1 (11%) | 10 (100%) | 10 (100%) | 8 (80%)
Necrosis | – | – | – | – | 1 (10%) | 10 (100%)
Ulcer | – | – | – | 1 (10%) | – | –
Lung | (10) | (10) | (10) | (10) | (10) | (10)
Bronchiole, goblet cell, hyperplasia | – | – | – | – | 4 (40%) | –
Bronchus, inflammation, chronic active | – | – | – | – | 1 (10%) | 6 (60%)
Bronchus, metaplasia, squamous | – | – | – | – | 1 (10%) | –
Bronchus, necrosis | – | – | – | – | 2 (20%) | 9 (90%)
Bronchus, regeneration | – | – | – | – | 1 (10%) | 1 (10%)
Perivascular, inflammation, chronic active | – | – | – | – | 1 (10%) | –
Nose | (10) | (10) | (10) | (10) | (10) | (10)
Inflammation, suppurative | – | 10 (100%) | 10 (100%) | 10 (100%) | 10 (100%) | 10 (100%)
Glands, olfactory epithelium, hyperplasia | – | 10 (100%) | 10 (100%) | 7 (70%) | 6 (60%) | –
Glands, respiratory epithelium, accumulation, hyaline droplet | – | 7 (70%) | 10 (100%) | 6 (60%) | – | –
Olfactory epithelium, accumulation, hyaline droplet | – | 10 (100%) | 10 (100%) | 10 (100%) | 9 (90%) | –
Olfactory epithelium, atrophy | – | 10 (100%) | 10 (100%) | 10 (100%) | 10 (100%) | 10 (100%)
Olfactory epithelium, metaplasia, respiratory | – | 1 (10%) | 8 (80%) | 10 (100%) | 4 (40%) | –
Olfactory epithelium, metaplasia, squamous | – | – | 2 (20%) | 1 (10%) | 2 (20%) | –
Olfactory epithelium, necrosis | – | – | – | – | – | 5 (50%)
Respiratory epithelium, accumulation, hyaline droplet | – | 10 (100%) | 10 (100%) | 10 (100%) | 10 (100%) | –
Respiratory epithelium, metaplasia, squamous | – | 10 (100%) | 10 (100%) | 10 (100%) | 10 (100%) | 6 (60%)
Respiratory epithelium, necrosis | – | 2 (20%) | 6 (60%) | 5 (50%) | 9 (90%) | 10 (100%)
Respiratory epithelium, regeneration | – | – | 1 (10%) | – | 1 (10%) | 4 (40%)
Respiratory epithelium, ulcer | – | – | 3 (30%) | – | – | –
Turbinate, atrophy | – | 4 (40%) | 6 (60%) | 10 (100%) | 8 (80%) | –
Trachea | (10) | (10) | (10) | (10) | (10) | (10)
Inflammation, chronic active | – | – | – | 1 (10%) | 9 (90%) | 10 (100%)
Metaplasia, squamous | – | – | – | 3 (30%) | 10 (100%) | 3 (30%)
Necrosis | – | – | – | – | – | 9 (90%)
Regeneration | – | – | – | – | – | 5 (50%)
Special Senses System
Eye | (10) | (10) | (10) | (10) | (10) | (10)
Cornea, inflammation, suppurative | – | 1 (10%) | – | – | 1 (10%) | 4 (40%)
Cornea, necrosis | – | – | – | – | 1 (10%) | –
Harderian gland | (10) | (0) | (0) | (10) | (10) | (10)
Urinary System
Kidney | (10) | (0) | (0) | (10) | (10) | (10)
Inflammation, chronic active | – | – | – | – | 1 (10%) | –
Nephropathy | 2 (20%) | – | – | 1 (10%) | 1 (10%) | –
Urinary bladder | (10) | (0) | (0) | (10) | (10) | (10)

^a^ Number of animals examined microscopically at the site and the number of animals with lesion.

Table A-4 Summary of the Incidence of Nonneoplastic Lesions in Female Mice in the Three-month Inhalation Study of o-Phthalaldehyde^a^

| Chamber Control | 0.44 ppm | 0.88 ppm | 1.75 ppm | 3.5 ppm | 7.0 ppm
Disposition Summary
Animals initially in study | 10 | 10 | 10 | 10 | 10 | 10
Early deaths
Moribund | – | – | – | – | 4 | 1
Natural deaths | – | – | – | – | – | 9
Survivors
Terminal euthanasia | 10 | 10 | 10 | 10 | 6 | –
Animals examined microscopically | 10 | 10 | 10 | 10 | 10 | 10
Alimentary System
Esophagus | (10) | (0) | (0) | (0) | (10) | (10)
Gallbladder | (10) | (0) | (0) | (0) | (9) | (1)
Intestine large, cecum | (10) | (0) | (0) | (0) | (10) | (4)
Intestine large, colon | (10) | (0) | (0) | (0) | (10) | (3)
Intestine large, rectum | (10) | (0) | (0) | (0) | (10) | (4)
Intestine small, duodenum | (10) | (0) | (0) | (0) | (10) | (2)
Intestine small, ileum | (10) | (0) | (0) | (0) | (10) | (2)
Intestine small, jejunum | (10) | (0) | (0) | (0) | (10) | (2)
Liver | (10) | (0) | (0) | (0) | (10) | (10)
Necrosis | – | – | – | – | 1 (10%) | –
Pancreas | (10) | (0) | (0) | (0) | (10) | (8)
Cyst | – | – | – | – | 1 (10%) | –
Salivary glands | (10) | (0) | (0) | (0) | (10) | (10)
Stomach, forestomach | (10) | (0) | (0) | (0) | (10) | (7)
Stomach, glandular | (10) | (0) | (0) | (0) | (10) | (7)
Cardiovascular System
Blood vessel | (10) | (0) | (0) | (0) | (9) | (0)
Heart | (10) | (0) | (0) | (0) | (10) | (10)
Endocrine System
Adrenal cortex | (10) | (0) | (0) | (1) | (10) | (10)
Adrenal medulla | (10) | (0) | (0) | (1) | (10) | (10)
Islets, pancreatic | (10) | (0) | (0) | (0) | (10) | (8)
Parathyroid gland | (6) | (0) | (0) | (0) | (5) | (4)
Pituitary gland | (10) | (0) | (0) | (0) | (10) | (7)
Thyroid gland | (10) | (0) | (0) | (0) | (10) | (10)
General Body System
None | – | – | – | – | – | –
Genital System
Clitoral gland | (9) | (0) | (0) | (0) | (8) | (8)
Ovary | (10) | (0) | (0) | (0) | (10) | (10)
Cyst | 1 (10%) | – | – | – | – | –
Uterus | (10) | (0) | (0) | (0) | (10) | (8)
Hematopoietic System
Bone marrow | (10) | (0) | (0) | (0) | (10) | (7)
Hyperplasia | – | – | – | – | 8 (80%) | –
Lymph node | (0) | (0) | (0) | (1) | (0) | (0)
Deep cervical, hyperplasia, lymphoid | – | – | – | 1 (100%) | – | –
Lymph node, bronchial | (4) | (0) | (0) | (0) | (6) | (7)
Lymph node, mandibular | (7) | (0) | (0) | (0) | (8) | (4)
Lymph node, mediastinal | (4) | (0) | (0) | (0) | (3) | (2)
Lymph node, mesenteric | (10) | (0) | (0) | (0) | (10) | (6)
Spleen | (10) | (0) | (0) | (0) | (10) | (8)
Atrophy, lymphoid | – | – | – | – | 1 (10%) | 8 (100%)
Thymus | (10) | (10) | (9) | (10) | (10) | (10)
Atrophy, lymphoid | – | – | – | – | 6 (60%) | 10 (100%)
Integumentary System
Mammary gland | (10) | (0) | (0) | (0) | (9) | (9)
Skin | (10) | (10) | (10) | (10) | (10) | (10)
Hyperplasia, squamous | 3 (30%) | – | – | 6 (60%) | 9 (90%) | 6 (60%)
Inflammation, chronic active | 1 (10%) | 1 (10%) | 3 (30%) | 9 (90%) | 9 (90%) | 8 (80%)
Adnexa, degeneration | 2 (20%) | – | – | 1 (10%) | – | 9 (90%)
Adnexa, pinna, degeneration | – | – | – | – | – | 10 (100%)
Epidermis, necrosis | – | – | – | – | – | 5 (50%)
Epithelium, hair follicle, parakeratosis | – | 3 (30%) | 7 (70%) | 9 (90%) | 10 (100%) | 10 (100%)
Epithelium, hair follicle, pinna, parakeratosis | – | – | – | – | – | 10 (100%)
Pinna, hyperplasia, squamous | – | – | – | – | – | 10 (100%)
Pinna, inflammation, chronic active | – | – | – | – | – | 10 (100%)
Musculoskeletal System
Bone | (10) | (0) | (0) | (0) | (10) | (10)
Nervous System
Brain | (10) | (0) | (0) | (0) | (10) | (10)
Respiratory System
Larynx | (10) | (10) | (10) | (10) | (10) | (10)
Inflammation, chronic active | – | – | – | – | 9 (90%) | 10 (100%)
Metaplasia, squamous | – | – | 3 (30%) | 10 (100%) | 10 (100%) | 8 (80%)
Necrosis | – | – | – | – | 3 (30%) | 9 (90%)
Regeneration | – | – | – | – | – | 3 (30%)
Ulcer | – | – | – | – | – | 1 (10%)
Lung | (10) | (10) | (10) | (10) | (10) | (10)
Bronchiole, goblet cell, hyperplasia | – | – | – | – | 6 (60%) | –
Bronchus, inflammation, chronic active | – | – | – | – | 6 (60%) | 8 (80%)
Bronchus, necrosis | – | – | – | – | 2 (20%) | 8 (80%)
Bronchus, regeneration | – | – | – | – | – | 1 (10%)
Bronchus, ulcer | – | – | – | – | – | 2 (20%)
Nose | (10) | (10) | (10) | (10) | (10) | (10)
Inflammation, suppurative | – | 10 (100%) | 10 (100%) | 10 (100%) | 10 (100%) | 6 (60%)
Glands, olfactory epithelium, hyperplasia | – | 10 (100%) | 9 (90%) | 10 (100%) | 8 (80%) | –
Glands, respiratory epithelium, accumulation, hyaline droplet | – | 9 (90%) | 10 (100%) | 6 (60%) | 2 (20%) | –
Olfactory epithelium, accumulation, hyaline droplet | – | 10 (100%) | 10 (100%) | 10 (100%) | 6 (60%) | –
Olfactory epithelium, atrophy | – | 10 (100%) | 10 (100%) | 10 (100%) | 9 (90%) | 9 (90%)
Olfactory epithelium, metaplasia, respiratory | – | 3 (30%) | 6 (60%) | 3 (30%) | 4 (40%) | –
Olfactory epithelium, necrosis | – | 1 (10%) | – | – | 1 (10%) | –
Olfactory epithelium, regeneration | – | – | – | – | 1 (10%) | –
Respiratory epithelium, accumulation, hyaline droplet | – | 10 (100%) | 10 (100%) | 10 (100%) | 8 (80%) | –
Respiratory epithelium, metaplasia,squamous | – | 10 (100%) | 10 (100%) | 10 (100%) | 8 (80%) | –
Respiratory epithelium, necrosis | – | 2 (20%) | 7 (70%) | 6 (60%) | 8 (80%) | 10 (100%)
Respiratory epithelium, regeneration | – | – | – | 1 (10%) | 3 (30%) | 6 (60%)
Respiratory epithelium, ulcer | – | – | – | – | – | 2 (20%)
Turbinate, atrophy | – | 7 (70%) | 9 (90%) | 10 (100%) | 7 (70%) | –
Trachea | (10) | (10) | (10) | (10) | (10) | (10)
Inflammation, chronic active | – | – | – | – | 10 (100%) | 10 (100%)
Metaplasia, squamous | – | – | – | – | 9 (90%) | 2 (20%)
Necrosis | – | – | – | – | 2 (20%) | 10 (100%)
Regeneration | – | – | – | – | 1 (10%) | 2 (20%)
Ulcer | – | – | – | – | 1 (10%) | –
Special Senses System
Eye | (10) | (10) | (10) | (10) | (10) | (8)
Cornea, inflammation, suppurative | – | – | – | – | 2 (20%) | 3 (38%)
Cornea, necrosis | – | – | – | – | – | 2 (25%)
Harderian gland | (10) | (0) | (0) | (0) | (10) | (9)
Urinary System
Kidney | (10) | (0) | (0) | (0) | (10) | (10)
Nephropathy | 1 (10%) | – | – | – | – | –
Urinary bladder | (10) | (0) | (0) | (0) | (10) | (9)

^a^ Number of animals examined microscopically at the site and the number of animals with lesion.