# Peer Review

The draft NTP Technical Report on the Toxicity Studies of o-Chloropyridine (CASRN 109-09-1) Administered Dermally and in Drinking Water to F344/N Rats and B6C3F1/N Mice was evaluated by the reviewers listed below. These reviewers served as independent scientists, not as representatives of any institution, company, or governmental agency. In this capacity, reviewers determined if the design and conditions of these NTP studies were appropriate and ensured that this NTP Toxicity Study Report presented the experimental results and conclusions fully and clearly.

## Peer Reviewers

- William J. Brock, Ph.D.
  Brock Scientific Consulting, LLC
  Montgomery Village, Maryland, USA
- Laura A. Hansen, Ph.D.
  Department of Biomedical Sciences
  Creighton University School of Medicine
  Omaha, Nebraska, USA
- Sandra A. James-Yi, D.V.M., Ph.D.
  Department of Biomedical Sciences and Pathobiology
  Virginia-Maryland College of Veterinary Medicine
  Virginia Tech
  Blacksburg, Virginia, USA