# Collaborators

- Division of the National Toxicology Program, National Institute of Environmental Health Sciences, Research Triangle Park, North Carolina, USA
  Evaluated and interpreted results and reported findings
  G.K. Roberts, Ph.D., Study Scientist
  S.A. Elmore, D.V.M., Study Pathologist
  C.R. Blystone, Ph.D.
  R.S. Chhabra, Ph.D.
  P.M. Foster, Ph.D.
  D.R. Germolec, Ph.D.
  M.J. Hooth, Ph.D.
  A.P. King-Herbert, D.V.M.
  G.E. Kissling, Ph.D.
  B.S. McIntyre, Ph.D.
  D.E. Malarkey, D.V.M., Ph.D.
  S.D. Peddada, Ph.D.
  S. Thakur, Ph.D.
  G.S. Travlos, D.V.M.
  M.K. Vallant, M.S., MT
  S. Waidyanatha, Ph.D.
  N.J. Walker, Ph.D.
  K.L. Witt, M.S.
- BioReliance Corporation, Rockville, Maryland, USA
  Conducted studies and evaluated pathology findings
  M.L. Wenk, Ph.D., Principal Investigator
  L.L. Lanning, D.V.M.
  G.B.J. Smith, Ph.D.
  D. Ragland, D.V.M.
- Experimental Pathology Laboratories, Inc., Research Triangle Park, North Carolina, USA
  Conducted pathology review
  N. Allison, D.V.M., Ph.D.
- ILS, Inc., Research Triangle Park, North Carolina, USA
  Coordinated NTP Pathology Working Group (October 6, 2005)
  P.E. Blackshear, D.V.M., Ph.D.
- TherImmune Research Corporation, Gaithersburg, Maryland, USA
  Provided SMVCE analysis
  G.W. Wolfe, Ph.D., Principal Investigator
  B. Atkinson, M.Sc.