# References

1 Lewis Reditor. Hawley’s condensed chemical dictionary. 13th ed. New York (NY): Van Nostrand Reinhold; 1997.
2 Lide D CRC handbook of chemistry and physics. 76th ed. Boca Raton (FL): CRC Press; 1995.
3 Reilly 5th edition product index. Indianapolis, IN: Reilly Industries, Inc; 1990.
4 Gehring P Pyridine, homologues and derivatives. In: Parneggiani Leditor. Encyclopedia of Occupational Health and Safety. 3rd revised ed. Geneva, Switzerland: International Labor Office; 1983. p. 1810–1812.
5 Goe G Kirk-Othmer Encyclopedia of Chemical Technology. 3rd ed. New York (NY): John Wiley and Sons; 1982. Pyridine and pyridine derivatives; p. 470.
6 Toomey J. inventor; Reilly Industries Inc, assignee. Pyridine chlorination process. United States patent no. WO 9413640 A1; 1994
7 Sharvit J, Lubetzky D, Pereferkovichm A. inventors; Makhteshim Chemical Works Limited, assignee. Process and catalysts for manufacture of chlorinated pyridines from alpha-picoline. Israel patent no. EP 239905 A1; 1987
8 Tamura M, Kasuga J, Watanabe N. inventors; Mitsubishi Kagaku Kk, assignee. Preparation of chloropyridines. Japan; 1995
9 United States International Trade Commission (USITC). Synthetic organic chemicals, U.S. production and sales. Washington, DC: Government Printing Office (GPO); 1994. USITC Publication No. 2810.
10 United States Environmental Protection Agency (USEPA). Toxic Substance Control Act chemical substances inventory. 2015. https://www.epa.gov/tsca-inventory [Accessed: July 29, 2015]
11 United States Environmental Protection Agency (USEPA). Initial risk-based prioritization of high production volume (HPV) chemicals. Washington, DC: United States Environmental Protection Agency (USEPA); 2009. https://www.epa.gov/hpvis/rbp/109-09-1_2-Chloropyridine_Web_April%202009.pdf
12 Kuney J. Chemcyclopedia 95 – The manual of commercially available chemicals. Washington, DC: The American Chemical Society. 1994; p. 194, 410.
13 Anonymous Olin doubles biocide precursor. Chem Mark Rep. 1996; 250:4.
14 Aldrich Catalog/Handbook of Fine Chemicals 1996-1997. Milwaukee (WI): Aldrich Chemical Co., Inc; 1996. p. 365.
15 Eastman Laboratory chemicals, catalog no. 55 93-94 ed. Rochester (NY): Eastman Chemical Company; 1993.
16 Acros organics 1995-1996 handbook of fine chemicals. Pittsburgh (PA): Fisher Scientific; 1995.
17 United States Environmental Protection Agency (USEPA). Industrial hygiene survey of Olin-Rochester with cover letter. Washington, DC: United States Environmental Protection Agency (USEPA); 1983. EPA/OTS: Doc #878220191.
18 National Institute for Occupational Safety and Health (NIOSH). National Occupational Exposure Survey (1981-1983) [unpublished provisional data]. Cincinnati, OH. 1990.
19 Gehring P Torkelson T Oyen F A comparison of the lethality of chlorinated pyridines and a study of the acute toxicity of 2-chloropyridine. Toxicol Appl Pharmacol. 1967; 11(2):361–371.http://dx.doi.org/10.1016/0041-008X(67)90079-8
20 Melcher R Bouyoucos S Membrane interface for automatic extraction and liquid chromatographic determination of trace organics in aqueous streams. Process Contr Qual. 1990; 1:63–74.
21 Guardiola A Ventura F Matia L Caixach J Rivera J Gas chromatographic-mass spectrometric characterization of volatile organic compounds in Barcelona tap water. J Chromatogr A. 1991;562(1-2):481–492. http://dx.doi.org/10.1016/0378-4347(91)80601-8 2026713
22 Hendriks A Maas-Diepeveen J Noordsij A Van der Gaag M Monitoring response of XAD-concentrated water in the Rhine delta: A major part of the toxic compounds remains unidentified. Water Res. 1994; 28(3):581–598.http://dx.doi.org/10.1016/0043-1354(94)90009-4
23 Liu SM Anaerobic dechlorination of chlorinated pyridines in anoxic freshwater sediment slurries. J Environ Sci Health A. 1995; 30(3):485–503.http://dx.doi.org/10.1080/10934529509376213
24 Adrian NR Suflita JM Anaerobic biodegradation of halogenated and nonhalogenated N‐, S‐, and O‐heterocyclic compounds in aquifer slurries. Environ Toxicol Chem. 1994; 13(10):1551–1557. 10.1002/etc.5620131002
25 American Conference of Governmental Industrial Hygienists (ACGIH). 2015 TLVs® and BEIs® based on the documentation of the threshold limit values for chemical substances and physical agents & biological exposure indices. Cincinnati, OH; 2015.
26 The book of chemical lists. Vol. 1. Madison (CT): Business and Legal Reports, Inc.; 1995.
27 Chłopkiewicz B Wójtowicz M Marczewska J Prokopczyk D Koziorowska J Contribution of N-oxidation and. OH radicals to mutagenesis of 2-chloropyridine in Salmonella typhimurium. Acta Biochim Pol. 1993; 40(1):57–59. 8396828
28 Claxton LD Dearfield KL Spanggord RJ Riccio ES Mortelmans K Comparative mutagenicity of halogenated pyridines in the Salmonella typhimurium/mammalian microsome test. Mutat Res. 1987; 176(2):185–198. http://dx.doi.org/10.1016/0027-5107(87)90049-2 3543664
29 Zimmermann FK Henning JH Scheel I Oehler M Genetic and anti-tubulin effects induced by pyridine derivatives. Mutat Res. 1986; 163(1):23–31. http://dx.doi.org/10.1016/0027-5107(86)90054-0 3528830
30 Anuszewska EL Koziorowska JH Role of pyridine N-oxide in the cytotoxicity and genotoxicity of chloropyridines. Toxicol In Vitro. 1995; 9(2):91–94. http://dx.doi.org/10.1016/0887-2333(94)00199-5 20650067
31 Dearfield KL Harrington-Brock K Doerr CL Parker L Moore MM Genotoxicity of three pyridine compounds to L5178Y mouse lymphoma cells. Mutat Res. 1993; 301(1):57–63. http://dx.doi.org/10.1016/0165-7992(93)90057-3 7677945
32 Simmon V Kauhanen K Tardiff R Mortelmans K Mutagenic activity of chemicals identified in drinking water. Mutat Res. 1978; 53(2):262.https://doi.org/10.1016/0165-1161(78)90337-0
33 National Toxicology Program (NTP). Toxicology and carcinogenesis studies of pyridine (CAS No. 110-86-1) in F344/N rats, Wistar rats, and B6C3F1 mice (drinking water studies). Research Triangle Park, NC: U.S. Department of Health and Human Services, Public Health Service, National Institutes of Health; 2000. Technical Report Series No. 470. NIH Publication No. 00-3960.
34 Maronpot RR Boorman GA Interpretation of rodent hepatocellular proliferative alterations and hepatocellular tumors in chemical safety assessment. Toxicol Pathol. 1982; 10(2):71–78. http://dx.doi.org/10.1177/019262338201000210 28094716
35 Boorman GA Montgomery CA Jr Eustis SL Wolfe MJ McConnell EE Hardisty JF Quality assurance in pathology for rodent carcinogenicity studies. In: Milman HA Weisburger EKeditors. Handbook of Carcinogen Testing. Park Ridge (NJ): Noyes Publications; 1985. p. 345–357.
36 Gart JJ Chu KC Tarone RE Statistical issues in interpretation of chronic bioassay tests for carcinogenicity. J Natl Cancer Inst. 1979; 62(4):957–974. 285297
37 Dunnett CW A multiple comparison procedure for comparing several treatments with a control. J Am Stat Assoc. 1955; 50(272):1096–1121.http://dx.doi.org/10.1080/01621459.1955.10501294
38 Williams DA The comparison of several dose levels with a zero dose control. Biometrics. 1972; 28(2):519–531. http://dx.doi.org/10.2307/2556164 5037867
39 Williams DA A test for differences between treatment means when several dose levels are compared with a zero dose control. Biometrics. 1971; 27(1):103–117. http://dx.doi.org/10.2307/2528930 5547548
40 Shirley E A non-parametric equivalent of Williams’ test for contrasting increasing dose levels of a treatment. Biometrics. 1977; 33(2):386–389. http://dx.doi.org/10.2307/2529789 884197
41 Williams DA A note on Shirley’s nonparametric test for comparing several dose levels with a zero-dose control. Biometrics. 1986; 42(1):183–186. http://dx.doi.org/10.2307/2531254 3719054
42 Dunn OJ Multiple comparisons using rank sums. Technometrics. 1964; 6(3):241–252.http://dx.doi.org/10.1080/00401706.1964.10490181
43 Jonckheere A A distribution-free k-sample test against ordered alternatives. Biometrika. 1954; 41:133–145. 10.1093/biomet/41.1-2.133
44 Dixon W Massey F Introduction to statistical analysis. New York (NY): McGraw Hill Book Company Inc; 1957.http://dx.doi.org/10.2307/2332898
45 Girard DM Sager DB The use of Markov chains to detect subtle variation in reproductive cycling. Biometrics. 1987;43(1):225–234. http://dx.doi.org/10.2307/2531963 3567307
46 Code of Federal Regulations (CFR). 21:Part 58.
47 Zeiger E Anderson B Haworth S Lawlor T Mortelmans K Salmonella mutagenicity tests: V. Results from the testing of 311 chemicals. Environ Mol Mutagen. 1992; 19 Suppl 21:2–141. http://dx.doi.org/10.1002/em.2850190603 1541260
48 MacGregor JT Wehr CM Henika PR Shelby MD The in vivo erythrocyte micronucleus test: measurement at steady state increases assay efficiency and permits integration with toxicity studies. Fundam Appl Toxicol. 1990; 14(3):513–522. http://dx.doi.org/10.1016/0272-0590(90)90255-I 2111256
49 Stockham S Scott M Erythrocytes. Fundamentals of veterinary clinical pathology. 2nd ed. Ames (IA): Blackwell Publishing; 2008. p. 107–221.
50 Klauder DS Petering HG Anemia of lead intoxication: a role for copper. J Nutr. 1977; 107(10):1779–1785. http://dx.doi.org/10.1093/jn/107.10.1779 903822
51 National Toxicology Program (NTP). Toxicity studies of cupric sulfate (CAS No. 7758-99-8) administered in drinking water and feed to F344/N rats and B6C3F1 mice. Research Triangle Park, NC: U.S. Department of Health and Human Services, Public Health Service, National Institutes of Health; 1993. Toxicity Report Series No. 29. NIH Publication No. 93-3352.
52 National Toxicology Program (NTP). Toxicity studies of estragole (CAS No. 140-67-0) administered by gavage to F344/N rats and B6C3F1 mice. Research Triangle Park, NC: U.S. Department of Health and Human Services, Public Health Service, National Institutes of Health; 2011. Toxicity Report Series No. 82. NIH Publication No. 11-5966.
53 Matuoka K Markus I Wong A Smith GJ Diethylnitrosamine- and partial hepatectomy-induced decrease in α 2u-globulin mRNA level in the rat liver. J Cancer Res Clin Oncol. 1993; 119(10):572–575. http://dx.doi.org/10.1007/BF01372719 7687602
54 National Toxicology Program (NTP). Toxicology and carcinogenesis studies of β-picoline (CAS No. 108 99-6) in F344/N rats and B6C3F1/N mice (drinking water studies). U.S. Department of Health and Human Services, Public Health Service, National Institutes of Health: Research Triangle Park, NC; 2014. Technical Report Series No. 580. NIH Publication No. 14-5922.
55 The Aldrich Library of 13C and 1H FT-NMR Spectra. Vol. 3. 1st ed. Milwaukee (WI): Aldrich Chemical Co., Inc.; 1992. p. 260C.
56 The Aldrich Library of FT-IR Spectra Spectrum 2. Vol. 2. 1st ed. Milwaukee (WI): Sigma-Aldrich Chemical Company; 1985. p. 746A.
57 The Aldrich library of infrared spectra. 3rd ed. Vol. 3, Spectrum 66B. Pouchert CJ, editor. Milwaukee, WI: Aldrich Chemical Company Inc.; 1981.
58 Talik Z. Chem Abstr. Roczniki Chemii. 1962; 36(59):1313–1320.
59 Beak P Lee JT Jr Equilibration studies. 2-(Methylthio) pyridine 1-methyl-2 (1H)-pyridinethione. J Org Chem. 1969; 34(7):2125–2128.http://dx.doi.org/10.1021/jo01259a021
60 Westland RD Cooley RA Jr Holmes JL Hong JS Lin MH Zwiesler ML Grenan MM Antiradiation agents. Substituted 2-pyridyloxy and 2-quinolyloxy derivatives of S-2-(ankylamino)ethyl hydrogen thiosulfates and 3-alkylthiazolidines and substituted 2-pyridyloxy derivatives of 2-(alkylamino)ethanethiols and corresponding disulfides. J Med Chem. 1973; 16(4):319–327. http://dx.doi.org/10.1021/jm00262a003 4716175
61 Kohrman R West D Little M The thermal deoxygenation of 2‐alkylthiopyridine 1‐oxides. J Heterocycl Chem. 1974;11(1):101–102.http://dx.doi.org/10.1002/jhet.5570110126
62 McKenna MC Bieri JG Multilayer cannula for long-term infusion of unrestrained rats. Lab Anim Sci. 1984; 34(3):308–310. 6748611
63 Gorrod JW Damani LA The metabolic N-oxidation of 3-substituted pyridines in various animal species in vivo. Eur J Drug Metab Pharmacokinet. 1980; 5(1):53–57. http://dx.doi.org/10.1007/BF03189445 7389753
64 Damani LA Crooks PA Shaker MS Caldwell J D’Souza J Smith RL Species differences in the metabolic C- and N-oxidation, and N-methylation of [14C]pyridine in vivo. Xenobiotica. 1982; 12(8):527–534. http://dx.doi.org/10.3109/00498258209038931 7147998
65 Shaker MS Crooks PA Damani LA High-performance liquid chromatographic analysis of the in vivo metabolites of [14C]pyridine. J Chromatogr A. 1982; 237(3):489–495. http://dx.doi.org/10.1016/S0021-9673(00)97638-6 7096490
66 D’Souza J Caldwell J Smith RL Species variations in the N-methylation and quaternization of [14C]pyridine. Xenobiotica. 1980; 10(2):151–157. http://dx.doi.org/10.3109/00498258009033741 7395267
67 Donaldson HH Conrow S Quantitative studies on the growth of the skeleton of the albino rat. Am J Anat. 1919; 26(2):236–314.http://dx.doi.org/10.1002/aja.1000260204
68 Adolph EF Quantitative relations in the physiological constitutions of mammals. Science. 1949; 109(2841):579–585. http://dx.doi.org/10.1126/science.109.2841.579 17835379
69 Supplee H Hauschildt JD Entenman C Plasma proteins and plasma volume in rats following total-body x-irradiation. Am J Physiol. 1952;169(2):438–490. http://dx.doi.org/10.1152/ajplegacy.1952.169.2.483 14933616
70 Caster WO Poncelet J Simon AB Armstrong WD Tissue weights of the rat. I. Normal values determined by dissection and chemical methods. Proc Soc Exp Biol Med. 1956; 91(1):122–126. http://dx.doi.org/10.3181/00379727-91-22186 13297726
71 Bischoff KB Dedrick RL Zaharko DS Longstreth JA Methotrexate pharmacokinetics. J Pharm Sci. 1971; 60(8):1128–1133. http://dx.doi.org/10.1002/jps.2600600803 5127083
72 Lutz RJ Dedrick RL Matthews HB Eling TE Anderson MW A preliminary pharmacokinetic model for several chlorinated biphenyls in the rat. Drug Metab Dispos. 1977; 5(4):386–396. 19218