# Discussion

o-Chloropyridine is used as a key intermediate for the manufacturing of pyrithione-based chemicals used in cosmetics and agriculture. It is also a starting material in the production of certain antihistamines and antiarrhythmic pharmaceuticals. In 2006, the production and import volume of o-chloropyridine in the United States was reported to range from 1 million to 10 million pounds.^11^ Occupational exposure can occur during the synthesis of o-chloropyridine and during its use as an industrial chemical intermediate. High vapor concentrations due to liquid spills have been detected in some industrial processing areas, suggesting the potential for significant exposure.^17^ Environmental exposure to o-chloropyridine is also possible; it has been found as a trace organic contaminant in process streams and wastewater as well as some drinking water sources.^20,21^ Despite the high production volume and potential for occupational and environmental exposure, there is little toxicity data available for this compound and no guidelines have been set by the National Institute for Occupational Safety and Health or the Occupational Safety and Health Administration. The current report describes the 2-week dermal and 3-month drinking water studies for o-chloropyridine administered to F344/N rats and B6C3F1/N mice. For the 3-month studies, the route of exposure was changed to drinking water, allowing for comparison of o-chloropyridine toxicity with the results of the NTP 3-month drinking water study of a structurally similar compound, pyridine.^33^ Toxicity targets of o-chloropyridine were similar across species and routes of exposure, including increased liver weight with accompanying histologic changes in the liver for the 3-month studies.

In the 2-week dermal studies, all rats and mice survived until the end of the study with no significant changes in body weights. Some significant changes in liver and kidney weights were observed, with no supporting histologic changes.

In the 3-month drinking water studies with o-chloropyridine, there was no effect on survival in rats or mice. The major findings in rats related to a possible inefficient erythropoiesis, evidenced by changes in erythron, bone marrow, and spleen. In mice, the major finding was greater liver weights, compared to controls, accompanied by centrilobular hepatocyte hypertrophy.

In the current 3-month drinking water study, significant changes, both increases and decreases, in hematology values were observed in male rats. On day 4, hematology results demonstrated an increase in circulating erythron (indicated by hematocrit, hemoglobin concentration, and erythrocytes) in 1,000 ppm male rats. This change was likely a physiologic response secondary to dehydration, due to a 50% decrease in water consumption. In addition, no changes in renal function were observed, indicated by creatinine concentration, supporting a dehydration hypothesis. Observations of exposure concentration-related and progressive hyperalbuminemia and hyperproteinemia should be considered a physiological response to dehydration and are unlikely to be a toxicologic response to o-chloropyridine.

While early changes in erythron were likely due to dehydration, by day 22, changes in hematocrit, hemoglobin, and erythrocytes were reversed, demonstrating a decrease in erythron that persisted until the end of the study. At week 14, an increase in reticulocyte count was also observed; these results together indicate an erythropoietic response that is further supported by increased incidences of hematopoietic cell proliferation and congestion in the spleen and hyperplasia of the bone marrow. The minimal microcytic, normochromic, and responsive erythron decreases observed on day 22 and at week 14 involved production of smaller erythrocytes and would indicate some mild exposure-related ineffective erythropoiesis potentially involving an alteration in iron availability/metabolism or the production or availability of heme or hemoglobin. Classically, microcytic erythron decreases have been associated with an iron deficiency.^49^ Because there was no clinical evidence of hemorrhage or blood loss, however, the microcytic change would suggest an ineffective erythropoiesis related to some alteration in iron and/or heme/hemoglobin metabolism. Such microcytic-type erythron decreases have been observed in rats with multiple agent types [e.g., lead^50^; cupric sulfate^51^; estragole^52^]. In fact, in the 3-month study of pyridine, a similar iron deficiency-like response occurred in rats.^33^ Mice demonstrated a similar decrease in erythron, although they appeared to be less sensitive, with effects seen only in high-dose females and without an observable erythropoietic response.

A decrease in the incidence and severity of hyaline droplet accumulation was observed in male rats in the 300 and 1,000 ppm groups. Hyaline droplets are normal lysosomal accumulations of α2u-globulin, a protein specific to male rats that is synthesized in the liver. Decreased synthesis of this protein by the liver may explain the decreased hyaline droplet accumulation that was observed. A study in rats treated with diethylnitrosamine reported a decrease in α2u-globulin mRNA in the liver, demonstrating that some chemicals are capable of affecting α2u-globulin synthesis.^53^ In the present study, α2u-globulin mRNA was not measured, however decreased synthesis of the α2u-globulin protein is a potential explanation for the lower hyaline droplet accumulation that was observed in male rat kidney.

In humans, it has been reported that the pathology associated with o-chloropyridine is similar to that of pyridine exposure. Acute, low-dose exposures, that do not cause clinical symptoms, have been associated with centrilobular fatty degeneration, congestion, and cellular infiltration in the liver; low-dose chronic exposures may lead to cirrhosis.^4^ In the current study, o-chloropyridine exposure in rats resulted in histopathologic lesions of the liver that may indicate a metabolic, adaptive response to treatment, including clear cell foci and hepatocyte cytoplasmic vacuolization. These changes were also observed in the 2-week dermal study with o-chloropyridine. While the liver was also a target in the pyridine 3-month drinking water study,^33^ the lesions produced in the F344/N rat were of a different nature, suggesting direct toxicity (centrilobular degeneration, hypertrophy, inflammation, and pigmentation). In addition to pyridine, NTP also performed a 3-month drinking water study in F344/N rats with a structurally similar compound, β-picoline, which targeted the kidney, resulting in increased severity of α2u-globulin-mediated nephropathy and produced no liver lesions.^54^ Large differences also exist in the bacterial mutagenicity of these three structurally similar compounds; o-chloropyridine is a potent bacterial mutagen while neither β-picoline nor pyridine is mutagenic.

Under the conditions of these 3-month drinking water studies, there were treatment-related organ weight changes and lesions in male and female rats and mice. The major target tissues in rats affected by o-chloropyridine exposure included the kidney, spleen, bone marrow, and liver; the major target organ in mice was the liver. The measurement most sensitive to o-chloropyridine exposure in male rats was increased absolute (all exposure groups) and relative (all exposure groups except 100 ppm) kidney weights in the absence of histopathologic changes [lowest-observed-effect level (LOEL) = 10 ppm]. In female rats, a LOEL of 10 ppm was based on splenic congestion, observed in all treated groups (except 30 ppm); with hematopoietic cell proliferation and pigmentation in the spleen, bone marrow hyperplasia, and hematological changes at higher exposure concentrations. This pattern of erythropoietic responses in the spleen and bone marrow and hematologic changes was also observed in male rats at 300 ppm or greater. In male mice, absolute and relative liver weights were significantly higher than controls in all exposed groups (LOEL 10 ppm), with histologic changes (centrilobular hepatocyte hypertrophy) occurring at 300 and 1,000 ppm. In female mice, absolute and relative liver weights were significantly greater than controls, with increased incidences of centrilobular hepatocyte hypertrophy occurring at similar exposure concentrations (LOEL 300 ppm).